# REFERENCES

1 Wisco BE, Nomamiukor FO, Marx BP, Krystal JH, Southwick SM, Pietrzak RH. Posttraumatic Stress Disorder in US Military Veterans: Results From the 2019–2020 National Health and Resilience in Veterans Study. J Clin Psychiatry. 2022;83(2). doi:10.4088/JCP.20m14029
2 Fulton JJ, Calhoun PS, Wagner HR, . The prevalence of posttraumatic stress disorder in Operation Enduring Freedom/Operation Iraqi Freedom (OEF/OIF) Veterans: A meta-analysis. J Anxiety Disord. 2015;31:98–107. doi:10.1016/j.janxdis.2015.02.003 25768399
3 Fang SC, Schnurr PP, Kulish AL, . Psychosocial Functioning and Health-Related Quality of Life Associated with Posttraumatic Stress Disorder in Male and Female Iraq and Afghanistan War Veterans: The VALOR Registry. J Womens Health. 2015;24(12):1038–1046. doi:10.1089/jwh.2014.5096
4 Brady KT, Killeen TK, Brewerton T, Lucerini S. Comorbidity of psychiatric disorders and posttraumatic stress disorder. J Clin Psychiatry. 2000;61 Suppl 7:22–32.
5 Levine AB, Levine LM, Levine TB. Posttraumatic Stress Disorder and Cardiometabolic Disease. Cardiology. 2014;127(1):1–19. doi:10.1159/000354910 24157651
6 Petrakis IL, Rosenheck R, Desai R. Substance Use Comorbidity among Veterans with Posttraumatic Stress Disorder and Other Psychiatric Illness: Substance Use Comorbidity among Veterans with PTSD. Am J Addict. 2011;20(3):185–189. doi:10.1111/j.1521-0391.2011.00126.x 21477045
7 Ramchand R, Rudavsky R, Grant S, Tanielian T, Jaycox L. Prevalence of, Risk Factors for, and Consequences of Posttraumatic Stress Disorder and Other Mental Health Problems in Military Populations Deployed to Iraq and Afghanistan. Curr Psychiatry Rep. 2015;17(5):37. doi:10.1007/s11920-015-0575-z 25876141
8 Cohen BE, Gima K, Bertenthal D, Kim S, Marmar CR, Seal KH. Mental Health Diagnoses and Utilization of VA Non-Mental Health Medical Services Among Returning Iraq and Afghanistan Veterans. J Gen Intern Med. 2010;25(1):18–24. doi:10.1007/s11606-009-1117-3
9 U.S. Department of Veterans Affairs VETERANS BENEFITS ADMINISTRATION Annual Benefits Report FISCAL YEAR 2023. https://www.benefits.va.gov/REPORTS/abr/docs/2023-abr.pdf#
10 Lang AJ, Hamblen JL, Holtzheimer P, . A clinician’s guide to the 2023 VA/DoD Clinical Practice Guideline for Management of Posttraumatic Stress Disorder and Acute Stress Disorder. J Trauma Stress. 2024;37(1):19–34. doi:10.1002/jts.23013 38184799
11 Karlin BE, Ruzek JI, Chard KM, . Dissemination of evidence-based psychological treatments for posttraumatic stress disorder in the Veterans Health Administration. J Trauma Stress. 2010;23(6):663–673. doi:10.1002/jts.20588 21171126
12 VHA DIRECTIVE 1160.01 UNIFORM MENTAL HEALTH SERVICES IN VHA MEDICAL POINTS OF SERVICE. Published online April 27, 2023. https://www.va.gov/vhapublications/ViewPublication.asp?pub_ID=10280
13 Goetter EM, Bui E, Ojserkis RA, Zakarian RJ, Brendel RW, Simon NM. A Systematic Review of Dropout From Psychotherapy for Posttraumatic Stress Disorder Among Iraq and Afghanistan Combat Veterans. J Trauma Stress. 2015;28(5):401–409. doi:10.1002/jts.22038 26375387
14 Hale AC, Bohnert KM, Ganoczy D, Sripada RK. Predictors of Treatment Adequacy During Evidence-Based Psychotherapy for PTSD. Psychiatr Serv. 2019;70(5):367–373. doi:10.1176/appi.ps.201800361 30784379
15 Kantor V, Knefel M, Lueger-Schuster B. Perceived barriers and facilitators of mental health service utilization in adult trauma survivors: A systematic review. Clin Psychol Rev. 2017;52:52–68. doi:10.1016/j.cpr.2016.12.001 28013081
16 Smith JR, Workneh A, Yaya S. Barriers and Facilitators to Help-Seeking for Individuals With Posttraumatic Stress Disorder: A Systematic Review. J Trauma Stress. 2020;33(2):137–150. doi:10.1002/jts.22456 31697863
17 Possemato K, Wray LO, Johnson E, Webster B, Beehler GP. Facilitators and Barriers to Seeking Mental Health Care Among Primary Care Veterans With Posttraumatic Stress Disorder. J Trauma Stress. 2018;31(5):742–752. doi:10.1002/jts.22327 30338576
18 Morland LA, Wells SY, Glassman LH, . What Do Veterans Want? Understanding Veterans’ Preferences for PTSD Treatment Delivery. Mil Med. 2019;184(11–12):686–692. doi:10.1093/milmed/usz035 30839067
19 Darkins A. The Growth of Telehealth Services in the Veterans Health Administration Between 1994 and 2014: A Study in the Diffusion of Innovation. Telemed E-Health. 2014;20(9):761–768. doi:10.1089/tmj.2014.0143
20 Calhoun PS, Beckham JC, Bosworth HB. Caregiver burden and psychological distress in partners of veterans with chronic posttraumatic stress disorder. J Trauma Stress. 2002;15(3):205–212. doi:10.1023/A:1015251210928 12092912
21 Beech EH, Young S, Anderson JK, Belsher BE, Parr NJ. Evidence Brief: Safety and Effectiveness of Telehealth-Delivered Mental Health Care. Department of Veterans Affairs (US); 2022. Accessed February 18, 2024. http://www.ncbi.nlm.nih.gov/books/NBK586283/
22 Kelber MS, Smolenski DJ, Boyd C, . Evidence-based telehealth interventions for posttraumatic stress disorder, depression, and anxiety: A systematic review and meta-analysis. J Telemed Telecare. Published online January 22, 2024:1357633X231224491. doi:10.1177/1357633X231224491
23 Andersson G. Using the Internet to provide cognitive behaviour therapy. Behav Res Ther. 2009;47(3):175–180. doi:10.1016/j.brat.2009.01.010 19230862
24 Lewis C, Roberts NP, Bethell A, Robertson L, Bisson JI. Internet-based cognitive and behavioural therapies for post-traumatic stress disorder (PTSD) in adults. Cochrane Common Mental Disorders Group, ed. Cochrane Database Syst Rev. Published online December 14, 2018. doi:10.1002/14651858.CD011710.pub2
25 Simon N, McGillivray L, Roberts NP, Barawi K, Lewis CE, Bisson JI. Acceptability of internet-based cognitive behavioural therapy (i-CBT) for post-traumatic stress disorder (PTSD): a systematic review. Eur J Psychotraumatology. 2019;10(1):1646092. doi:10.1080/20008198.2019.1646092
26 Clough BA, Casey LM. The smart therapist: A look to the future of smartphones and mHealth technologies in psychotherapy. Prof Psychol Res Pract. 2015;46(3):147–153. doi:10.1037/pro0000011
27 Goreis A, Felnhofer A, Kafka JX, Probst T, Kothgassner OD. Efficacy of Self-Management Smartphone-Based Apps for Post-traumatic Stress Disorder Symptoms: A Systematic Review and Meta-Analysis. Front Neurosci. 2020;14:3. doi:10.3389/fnins.2020.00003 32038153
28 Wickersham A, Petrides PM, Williamson V, Leightley D. Efficacy of mobile application interventions for the treatment of post-traumatic stress disorder: A systematic review. Digit Health. 2019;5:205520761984298. doi:10.1177/2055207619842986
29 Linardon J, Torous J, Firth J, Cuijpers P, Messer M, Fuller-Tyszkiewicz M. Current evidence on the efficacy of mental health smartphone apps for symptoms of depression and anxiety. A meta-analysis of 176 randomized controlled trials. World Psychiatry. 2024;23(1):139–149. doi:10.1002/wps.21183 38214614
30 Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Published online August 28, 2019:l4898. doi:10.1136/bmj.l4898 31462531
31 Sterne JA, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. Published online October 12, 2016:i4919. doi:10.1136/bmj.i4919 27733354
32 Slavin RE. Best evidence synthesis: An intelligent alternative to meta-analysis. J Clin Epidemiol. 1995;48(1):9–18. doi:10.1016/0895-4356(94)00097-A 7853053
33 Viechtbauer W. metafor: Meta-analysis package for R. Published online 2023. https://cran.r-project.org/web/packages/metafor/index.html
34 Parr NJ, Schweer-Collins ML, Darlington TM, Tanner-Smith EE. Meta-analytic approaches for examining complexity and heterogeneity in studies of adolescent development. J Adolesc. 2019;77(1):168–178. doi:10.1016/j.adolescence.2019.10.009 31739275
35 Berkman ND, Lohr KN, Ansari M, . Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. In: Methods Guide for Effectiveness and Comparative Effectiveness Reviews. AHRQ Methods for Effective Health Care. Agency for Healthcare Research and Quality (US); 2008. Accessed August 8, 2023. http://www.ncbi.nlm.nih.gov/books/NBK174881/
36 Acosta MC, Possemato K, Maisto SA, . Web-Delivered CBT Reduces Heavy Drinking in OEF-OIF Veterans in Primary Care With Symptomatic Substance Use and PTSD. Behav Ther. 2017;48(2):262–276. doi:10.1016/j.beth.2016.09.001 28270335
37 Allen AR, Smith J, Hobbs MJ, . Internet-delivered cognitive behaviour therapy for post-traumatic stress disorder: a randomised controlled trial and outcomes in routine care. Behav Cogn Psychother. 2022;50(6):649–655. doi:10.1017/S1352465822000285 35924312
38 Andersson G, Olsson E, Ringsgard E, . Individually tailored Internet-delivered cognitive-behavioral therapy for survivors of intimate partner violence: A randomized controlled pilot trial. Internet Interv. 2021;26(101631612):100453. doi:10.1016/j.invent.2021.100453 34584851
39 Bedard-Gilligan MA, Dworkin ER, Kaysen D, Ojalehto HJ, Stappenbeck CA, Lindgren KP. A pilot study on the feasibility, acceptability, and preliminary efficacy of a brief text message intervention for co-occurring alcohol misuse and PTSD symptoms in a community sample. J Anxiety Disord. 2022;91(co1, 8710131):102615. doi:10.1016/j.janxdis.2022.102615 35988440
40 Bedford CE, Schmidt NB. Efficacy of a novel safety behavior elimination intervention for posttraumatic stress symptoms: Results from a randomized controlled trial. J Affect Disord. 2023;339(h3v, 7906073):640–647. doi:10.1016/j.jad.2023.07.002 37442451
41 Bisson JI, Ariti C, Cullen K, . Guided, internet based, cognitive behavioural therapy for post-traumatic stress disorder: pragmatic, multicentre, randomised controlled non-inferiority trial (RAPID). BMJ. 2022;377(8900488, bmj, 101090866):e069405. doi:10.1136/bmj-2021-069405 35710124
42 Clausen AN, Thelen J, Francisco AJ, . Computer-Based Executive Function Training for Combat Veterans With PTSD: A Pilot Clinical Trial Assessing Feasibility and Predictors of Dropout. Front Psychiatry. 2019;10(101545006):62. doi:10.3389/fpsyt.2019.00062 30881315
43 de Kleine RA, Woud ML, Ferentzi H, . Appraisal-based cognitive bias modification in patients with posttraumatic stress disorder: a randomised clinical trial. Eur J Psychotraumatology. 2019;10(1):1625690. doi:10.1080/20008198.2019.1625690
44 Engel CC, Litz B, Magruder KM, . Delivery of self training and education for stressful situations (DESTRESS-PC): a randomized trial of nurse assisted online self-management for PTSD in primary care. Gen Hosp Psychiatry. 2015;37(4):323–328. doi:10.1016/j.genhosppsych.2015.04.007 25929985
45 Fonzo GA, Fine NB, Wright RN, . Internet-delivered computerized cognitive & affective remediation training for the treatment of acute and chronic posttraumatic stress disorder: Two randomized clinical trials. J Psychiatr Res. 2019;115(jtj, 0376331):82–89. doi:10.1016/j.jpsychires.2019.05.007 31125916
46 Gawlytta R, Kesselmeier M, Scherag A, . Internet-based cognitive-behavioural writing therapy for reducing post-traumatic stress after severe sepsis in patients and their spouses (REPAIR): results of a randomised-controlled trial. BMJ Open. 2022;12(3):e050305. doi:10.1136/bmjopen-2021-050305
47 Hensler I, Sveen J, Cernvall M, Arnberg FK. Efficacy, Benefits, and Harms of a Self-management App in a Swedish Trauma-Exposed Community Sample (PTSD Coach): Randomized Controlled Trial. J Med Internet Res. 2022;24(3):e31419. doi:10.2196/31419 35353052
48 Hirai M, Dolma S, Vernon LL, Clum GA. A longitudinal investigation of the efficacy of online expressive writing interventions for Hispanic students exposed to traumatic events: competing theories of action. Psychol Health. 2020;35(12):1459–1476. doi:10.1080/08870446.2020.1758324 32362147
49 Ivarsson D, Blom M, Hesser H, . Guided internet-delivered cognitive behavior therapy for post-traumatic stress disorder: a randomized controlled trial. 2014;1(1):33–40. doi:10.1016/j.invent.2014.03.002
50 Knaevelsrud C, Maercker A. Internet-based treatment for PTSD reduces distress and facilitates the development of a strong therapeutic alliance: a randomized controlled clinical trial. BMC Psychiatry. 2007;7(100968559):13.17442125
51 Krupnick JL, Green BL, Amdur R, . An Internet-based writing intervention for PTSD in veterans: A feasibility and pilot effectiveness trial. Psychol Trauma Theory Res Pract Policy. 2017;9(4):461–470. doi:10.1037/tra0000176
52 Kuhn E, Kanuri N, Hoffman JE, Garvert DW, Ruzek JI, Taylor CB. A randomized controlled trial of a smartphone app for posttraumatic stress disorder symptoms. J Consult Clin Psychol. 2017;85(3):267–273. doi:10.1037/ccp0000163 28221061
53 Lange A, Rietdijk D, Hudcovicova M, van de Ven JP, Schrieken B, Emmelkamp PMG. Interapy: a controlled randomized trial of the standardized treatment of posttraumatic stress through the internet. J Consult Clin Psychol. 2003;71(5):901–909.14516238
54 Larsen SE, Lotfi S, Bennett KP, Larson CL, Dean-Bernhoft C, Lee HJ. A pilot randomized trial of a dual n-back emotional working memory training program for veterans with elevated PTSD symptoms. Psychiatry Res. 2019;275(qc4, 7911385):261–268. doi:10.1016/j.psychres.2019.02.015 30939398
55 Lehavot K, Millard SP, Thomas RM, . A randomized trial of an online, coach-assisted self-management PTSD intervention tailored for women veterans. J Consult Clin Psychol. 2021;89(2):134–142. doi:10.1037/ccp0000556 33705169
56 Lewis CE, Farewell D, Groves V, . Internet-based guided self-help for posttraumatic stress disorder (PTSD): Randomized controlled trial. Depress Anxiety. 2017;34(6):555–565. doi:10.1002/da.22645 28557299
57 Littleton H, Grills AE, Kline KD, Schoemann AM, Dodd JC. The From Survivor to Thriver program: RCT of an online therapist-facilitated program for rape-related PTSD. J Anxiety Disord. 2016;43(co1, 8710131):41–51. doi:10.1016/j.janxdis.2016.07.010 27513363
58 Litz BT, Engel CC, Bryant RA, Papa A. A randomized, controlled proof-of-concept trial of an Internet-based, therapist-assisted self-management treatment for posttraumatic stress disorder. Am J Psychiatry. 2007;164(11):1676–1683.17974932
59 McGuire AP, Howard BAN, Erickson TM, Creech SK. Moral Elevation Online Intervention for Veterans Experiencing Distress Related to Posttraumatic Stress Disorder and Moral Injury (MOVED): Pilot Trial of a 4-Week Positive Psychology Web-Based Intervention. JMIR Form Res. 2023;7(101726394):e39894. doi:10.2196/39894 36961494
60 McLean CP, Foa EB, Dondanville KA, . The effects of web-prolonged exposure among military personnel and veterans with posttraumatic stress disorder. Psychol Trauma Theory Res Pract Policy. 2021;13(6):621–631. doi:10.1037/tra0000978
61 McLean C, Davis CA, Miller M, Ruzek J, Neri E. The Effects of an Exposure-Based Mobile App on Symptoms of Posttraumatic Stress Disorder in Veterans: Pilot Randomized Controlled Trial. JMIR MHealth UHealth. 2022;10(11):e38951. doi:10.2196/38951 36331540
62 Miner A, Kuhn E, Hoffman JE, Owen JE, Ruzek JI, Taylor CB. Feasibility, acceptability, and potential efficacy of the PTSD Coach app: A pilot randomized controlled trial with community trauma survivors. Psychol Trauma Theory Res Pract Policy. 2016;8(3):384–392. doi:10.1037/tra0000092
63 Morabito DM, Schmidt NB. Efficacy of a brief web-based tonic immobility psychoeducation intervention among trauma-exposed adults: A randomized clinical trial. J Trauma Stress. 2023;(b1b, 8809259). doi:10.1002/jts.22955
64 Nieminen K, Berg I, Frankenstein K, . Internet-provided cognitive behaviour therapy of posttraumatic stress symptoms following childbirth—a randomized controlled trial. Cogn Behav Ther. 2016;45(4):287–306. doi:10.1080/16506073.2016.1169626 27152849
65 Possemato K, Ouimette P, Knowlton P. A brief self-guided telehealth intervention for posttraumatic stress disorder in combat veterans: a pilot study. J Telemed Telecare. 2011;17(5):245–250. doi:10.1258/jtt.2011.100909 21636687
66 Possemato K, Kuhn E, Johnson E, . Using PTSD Coach in primary care with and without clinician support: a pilot randomized controlled trial. Gen Hosp Psychiatry. 2016;38(fnk, 7905527):94–98. doi:10.1016/j.genhosppsych.2015.09.005 26589765
67 Possemato K, Johnson EM, Emery JB, . A pilot study comparing peer supported web-based CBT to self-managed web CBT for primary care veterans with PTSD and hazardous alcohol use. Psychiatr Rehabil J. 2019;42(3):305–313. doi:10.1037/prj0000334 30489140
68 Spence J, Titov N, Dear BF, . Randomized controlled trial of Internet-delivered cognitive behavioral therapy for posttraumatic stress disorder. Depress Anxiety. 2011;28(7):541–550. doi:10.1002/da.20835 21721073
69 Spence J, Titov N, Johnston L, Jones MP, Dear BF, Solley K. Internet-based trauma-focused cognitive behavioural therapy for PTSD with and without exposure components: a randomised controlled trial. J Affect Disord. 2014;162(h3v, 7906073):73–80. doi:10.1016/j.jad.2014.03.009 24767009
70 McCall H, Dear BF, Landry C, . Internet-delivered cognitive behavioural therapy for symptoms of PTSD among public safety personnel: Initial outcomes of an open cohort preference trial of transdiagnostic and disorder-specific therapy. Internet Interv. 2023;33(101631612):100656. doi:10.1016/j.invent.2023.100656 37609530
71 Wiltsey Stirman S, Song J, Hull TD, Resick PA. Open trial of an adaptation of cognitive processing therapy for message-based delivery. Technol Mind Behav. 2021;2(1):No-Specified. doi:10.1037/tmb0000016
72 Erbes CR, Kuhn E, Polusny MA, . A Pilot Trial of Online Training for Family Well-Being and Veteran Treatment Initiation for PTSD. Mil Med. 2020;185(3–4):401–408. doi:10.1093/milmed/usz326 31621884
73 van Stolk-Cooke K, Wielgosz J, Hallenbeck HW, . The PTSD Family Coach App in Veteran Family Members: Pilot Randomized Controlled Trial. JMIR Form Res. 2023;7(101726394):e42053. doi:10.2196/42053 36602852
74 Crenshaw AO, Whitfield KM, Collins A, . Partner outcomes from an uncontrolled trial of Couple HOPES: A guided online couple intervention for posttraumatic stress disorder and relationship enhancement. J Trauma Stress. 2023;36(1):230–238. doi:10.1002/jts.22878 36116104
75 Kuhn E, Sayers SL, Babusci C, Conroy C, Erbes CR. Internet-based family training with telephone coaching to promote mental health treatment initiation among veterans with posttraumatic stress disorder: A pilot study. J Trauma Stress. 2023;36(3):549–556. doi:10.1002/jts.22900 36562921
76 Morland LA, Wachsman T, Webster K, . A pilot of couple HOPES within the U.S. Veterans Affairs Healthcare System: PTSD and relationship outcomes in veteran couples. Psychol Serv. 2023;(101214316). doi:10.1037/ser0000773
77 Hensler I, Sveen J, Cernvall M, Arnberg FK. Longitudinal follow-up of the randomized controlled trial of access to the trauma-focused self-management app PTSD Coach. Internet Interv. 2023;32(101631612):100618. doi:10.1016/j.invent.2023.100618 37273938
78 Jacoby VM, Straud CL, Bagley JM, . Evidence-based posttraumatic stress disorder treatment in a community sample: Military-affiliated versus civilian patient outcomes. J Trauma Stress. 2022;35(4):1072–1086. doi:10.1002/jts.22812 35201657
79 Newman MG, Szkodny LE, Llera SJ, Przeworski A. A review of technology-assisted self-help and minimal contact therapies for anxiety and depression: Is human contact necessary for therapeutic efficacy? Clin Psychol Rev. 2011;31(1):89–103. doi:10.1016/j.cpr.2010.09.008 21130939