# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson, MLS, MS for literature searching and screening support, Payten Higgins for editorial, citation management, screening, and data abstraction support, Sarah Young, MPH for screening and data abstraction support, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Jessica Hamblen, PhD
  Deputy Director for Education
  National Center for PTSD
- Paul Holtzheimer, MD
  Deputy Director for Research
  National Center for PTSD
- Peter Hunt, PhD
  Scientific Program Manager
  Office of Research and Development