# DISCUSSION

Self-guided, asynchronous PTSD treatments that utilize internet or mobile phone technology have developed rapidly over the past 2 decades. These treatments can be delivered remotely to patients and require variable therapeutic support, potentially expanding access to PTSD treatments for adults with PTSD and their caregivers. The current systematic review examined the effectiveness of internet and mobile interventions for adults with PTSD. Primary outcomes were analyzed separately for civilian and military (Veterans or active-duty service members) populations. The effectiveness of internet and mobile interventions for caregivers and family members of adults with PTSD was also evaluated.

Our primary results indicated differential effectiveness of treatments for civilian and military populations. Internet and mobile interventions may be moderately effective in reducing PTSD and depression severity in civilians, immediately post-treatment. In contrast, military populations treated with internet or mobile interventions experienced small to negligible benefits. For both populations, no treatment effects were evident at shorter and longer-term follow-up periods. Based on available evidence, internet and mobile interventions may increase the odds of clinically meaningful PTSD symptom improvement post-treatment among civilian but not military populations. We have low confidence in these findings based on study methodological limitations, imprecision, and moderate inconsistency.

Findings that internet and mobile interventions for PTSD may have limited benefits in military populations are consistent with prior research that has shown that PTSD can be less responsive to treatment in military populations compared with civilians.^78^ However, differences in study designs and intervention characteristics limit our ability to make strong conclusions about the effectiveness or ineffectiveness of the interventions among Veterans and active duty military personnel. Future studies might explore whether internet and mobile resources have a beneficial role in supporting the established VA clinical pathway for PTSD, for example to improve treatment adherence or facilitate at-home activities that reinforce principles and practices introduced during in-person therapy.

We further explored how intervention and study factors may impact treatment effectiveness. Research has shown that integrating therapist involvement in digital interventions increases treatment effectiveness.^66,79^ Our results are consistent with this finding and indicated that direct facilitation had the largest benefits on treatment outcomes, followed by minimal facilitation. Interventions with no active provider support showed the least benefit for both depression and PTS severity. In one large civilian trial (N = 196), trauma-focused iCBT with a high level of direct therapeutic support (avg of 3.5 hours/participant) was non-inferior to an established face-to-face PTSD treatment for treatment-naïve patients.^41^ Exploring the appropriate level of therapeutic support (who and how much) is an important consideration in any implementation effort and should take into account the targeted population and anticipated reach of the intervention, desired effectiveness, and available health system resources.

Trauma-focused CBT treatments for PTSD are recommended as first-line treatments in clinical practice guidelines based on the current evidence.^10^ Only 4 of the 13 included studies on a military sample evaluated a trauma-focused CBT. Two of these were based on PE^60,61^ and 2 utilized approaches based on written exposure therapy (WET).^51,65^ Most of these studies included a small sample size and had high drop-out rates or low treatment engagement rates. Across all 4 studies, there were nonsignificant differences on PTSD severity between treatment arms at post-treatment. In comparison, over 60% of the civilian studies evaluated a trauma-focused CBT. In addition to written exposure paradigms, these treatments also included several iCBT interventions that incorporated multiple trauma-focused treatment components (ie, in vivo and imaginal exposure; cognitive restructuring, grounding and relaxation exercises). Our subgroup analyses did not show that inclusion of written exposure contributed to improved treatment effectiveness, but there are other relevant trauma-focused treatment components worth exploring in future research. Given the promising effects of iCBT in civilians, future studies on military populations may benefit from incorporating similar treatment approaches.^41,56^ Further, none of the trauma-focused CBTs in the military population incorporated direct therapist involvement. Based on the promising results of civilian studies that incorporated direct facilitation with trauma-focused CBT interventions,^41,56^ future military trials may want to investigate whether increasing levels of provider involvement impacts treatment retention and effectiveness. Examining the cost-effectiveness of increasing provider support relative to offering traditional face-to-face trauma-focused treatments would need to be a consideration.

Treatment benefits were largest when interventions were compared with a completely inactive condition like waitlist control, and small to negligible when compared to more active treatment condition. An exception to this finding was the previously mentioned study in which iCBT with a high level of therapeutic support demonstrated non-inferiority to in-person PTSD treatment.^41^ Treatment effects were also larger against lower-intensity comparator interventions (eg, psychoeducation). Internet and online interventions may still play a role in increasing treatment access for those patients who are unable or unwilling to engage in a trauma-focused treatment. Future studies should explore whether internet or mobile PTSD interventions have an impact on the care pathway for patients at different levels of treatment engagement.

It is unclear whether internet and mobile interventions for caregivers and family members of adults with PTSD improve any mental health outcomes. Only 5 studies were identified and included that evaluated an internet or mobile intervention for caregivers or family members of an adult with PTSD. We examined 4 different outcomes that were assessed in at least 2 of the studies: caregiver burden, depression, anxiety, and quality of life. There was some indication that treatments may reduce caregiver burden and improve quality of life, but findings were inconsistent across individual trials. Given the study limitations, inconsistent findings across outcomes, and unknown precision, we have low confidence in these findings.

Limitations

There are several limitations to this review that are worth noting. Many of the included studies were small pilot trials testing the feasibility and acceptability of the online intervention and were likely inadequately powered to detect all but the largest treatment effects. There were only 4 military studies that evaluated a trauma-focused CBT, and these treatments were based on specific trauma treatments. Thus, we are unable to conclude whether our findings would generalize to other forms of trauma-focused iCBT interventions. Most studies used self-assessments to determine PTSD status and treatment outcomes rather than clinician-administered measures. Inclusion criteria in many studies did not require a full PTSD diagnosis and so the included sample often included participants with subthreshold PTSD symptoms. Although most studies included Veterans in their samples, a substantial proportion of participants were treatment-seeking White females, which may limit the applicability of findings to the VA population.

## FUTURE RESEARCH

Recommendations for future research on internet and mobile interventions for PTSD include the following:

- Evaluate whether trauma-focused iCBTs that integrate direct therapeutic support increase treatment retention and effectiveness for military populations. Examining the cost-effectiveness of increasing provider support relative to offering traditional face-to-face trauma-focused treatments would need to be a consideration.
- Examine whether iCBTs may be differentially effective for specific military populations. For instance, do internet interventions for treatment-naïve veterans with less complex symptom presentations demonstrate better results?
- Explore whether internet and mobile resources have a beneficial role in supporting the established VA clinical pathway for PTSD, for example to improve treatment adherence or facilitate at-home activities that reinforce principles and practices introduced during in-person therapy.
- Characterize factors that influence Veteran engagement in internet and mobile interventions, such as technology literacy or internet access, and evaluate strategies to maintain adherence.
- Evaluate the appropriate level of therapeutic training and specific competencies necessary for providers to successfully support patient engagement in iCBTs.
- Examine components of internet and mobile interventions to identify whether certain trauma-focused CBT interventions have a greater influence on treatment outcomes.

## CONCLUSIONS

Internet and mobile interventions for PTSD have the potential to expand access to PTSD treatments for adults with PTSD and their caregivers. The current review examined the effectiveness of these digital treatments and explored treatment factors that may impact implementation considerations. Results indicated that civilians may experience moderate benefits from these interventions at post-treatment, but military populations experience small to negligible benefits on PTSD and depression outcomes. Treatment effects for both populations are not sustained at shorter and longer-term follow-up periods. Consistent with previous research, level of facilitation could be a key factor in the effectiveness of internet and mobile interventions for PTSD. Internet and mobile interventions do not appear to benefit family members of adults with PTSD. Currently, available evidence does not support the use of internet and mobile interventions as a replacement for first-line, in-person treatments for PTSD. Future studies could explore whether internet and mobile resources have a beneficial role in supporting the established VA clinical pathway for PTSD, including whether they improve treatment engagement for Veterans who are unable or unwilling to engage in trauma-focused therapies.