# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

Notes. ^a^ 60 primary studies in 63 records.

Abbreviations. CCRCT=Cochrane Central Register of Controlled Trials.

## OVERVIEW OF INCLUDED STUDIES

Our search identified 222 potentially relevant articles after deduplication and title and abstract screening. We included 60 primary studies (in 63 publications) meeting eligibility criteria: 36 RCTs, 1 non-randomized trial, 1 cohort study, and 22 pre-post studies. We prioritized evidence from comparative studies, and did not include pre-post studies in our synthesis, except for pre-post studies on family members/caregivers, where few comparative studies were available. Characteristics of prioritized studies are shown in Table 1. We identified 35 underway studies (see Appendix).

### PTSD Studies

Of the studies prioritized for synthesis (N = 36), 34 were RCTs,^36–69^ 1 was a non-randomized trial,^70^ and 1 was a cohort study.^71^ Most were conducted in the US (N = 22), with the remaining studies conducted in Sweden (N = 4), the Netherlands (N = 3), Australia (N = 3), Canada (N = 1), Germany (N = 1), and the UK (N = 2). Sample sizes ranged from 20-196 (median = 63). Two-thirds of the studies had predominately female samples. Of the studies that reported on race or ethnicity (N = 23), all but 3^48,59,60^ had predominately White samples. Thirteen studies^36,42,44,51,54,55,58–61,65–67^ were conducted with US Veterans or military Service members. Among these, 10 studies^36,42,51,54,55,59,61,65–67^ were conducted exclusively among Veterans and 7^36,51,55,59,65–67^ were conducted exclusively among Veterans enrolled in Veterans Health Administration (VHA) care or recruited from VHA health care settings. The proportion of study participants meeting criteria for a PTSD diagnosis or probable/provisional PTSD diagnosis was 100% in 21 studies, between 75-99% in 5 studies, and between 48-74% in 8 studies (exact proportions were not reported for 2 studies). PTSD diagnostic status was determined by a structured clinical interview using the gold standard Clinician-Administered PTSD Scale (CAPS) in 9 studies. Most studies used a version of the PTSD Checklist (PCL) to establish a provisional PTSD diagnosis, with cut-off scores varying across studies. Other measures used included the Mini International Neuropsychiatric Interview (MINI), the Posttraumatic Symptom Scale (interview or self-report version; PSS-I or PSS-SR), and the revised Impact of Events Scale (IES-R).

Most studies (N = 30) evaluated internet interventions, 5 studies^47,52,61,62,66^ evaluated mobile app interventions, and a single study^39^ evaluated a text messaging (SMS) intervention. Most interventions were CBT-based (N = 32), and 18 studies specifically evaluated a trauma-focused CBT. Among civilian studies, 14 evaluated a trauma-focused CBT; among military studies, 4 studies tested a trauma-focused CBT. In the military trials, trauma-focused CBT interventions were either based on prolonged exposure (PE)^60,61^ or written exposure.^51,65^ Other interventions were based on executive function training (N = 3)^42,45,54^ or goal setting (N = 1).^59^ Over half of studies (21) investigated long-duration interventions (6 or more weeks); moderate-duration interventions (2-5 weeks) were examined in 6 studies and brief interventions (1 week or less or a single session) in 5 studies. Interventions used a self-guided timeline in 4 studies. Fifteen studies evaluated interventions that included provider guidance and/or feedback, and 6 studies evaluated interventions with some direct facilitation (ie, delivery of intervention content) by a provider. The remaining studies (N = 15) evaluated self-guided interventions with no provider involvement other than reminders and/or technical support. Provider involvement was primarily asynchronous in 8 studies, primarily synchronous in 5 studies, and a combination of both in 7 studies.

Nineteen studies compared an intervention to an alternative intervention. For example, an intervention may have been compared to the same intervention without 1 or more components (eg, with and without therapist guidance) or to psychoeducation. Two studies^41,60^ compared the intervention to synchronous in-person therapy. Other comparators included a waitlist (N = 13), treatment as usual (TAU; N = 3), and minimal contact (ie, phone monitoring or assessments only; N = 2).

PTSD symptom severity was most often assessed with a version of the PCL (PCL-M, N = 5; PCL-C, N = 5; PCL-5, N = 14; PCL-S, N = 1). Other measures used included the CAPS-5 (N = 4), PDS (N = 2), IES/IES-R (N = 7), PC-PTSD (N = 1), PSS-SR (N = 1), PSS-I (N = 3), and TES (N = 1). In addition to symptom severity, 10 studies reported on clinically significant improvement, 10 studies reported on remission, recovery, or no longer meeting PTSD criteria, and 6 studies reported on reliable improvement or change. Other mental health outcomes reported by more than 1 study included depression (N = 23), generalized anxiety (N = 16), alcohol use (N = 6), somatic symptoms (N = 3), and psychological distress (N = 2). Drug use, stress, panic disorder symptoms, social phobia/social anxiety symptoms, anger, and moral injury-related distress were each reported by a single study. Quality of life outcomes were reported by 10 studies, and 8 studies reported outcomes related to functioning.

Common methodological limitations of RCTs were small sample sizes, low treatment adherence, limited information on randomization and co-interventions, lack of blinding of participants and outcome assessors, and analyses that did not include all randomized participants. Common methodological limitations of non-randomized studies were low treatment adherence, a high degree of missing data, lack of information on co-interventions, and use of analyses that do not account for potential confounders.

### Family Member/Caregiver Studies

Among studies evaluating interventions for family members or caregivers of adults with PTSD (Key Question 2; N = 5), 2 were RCTs^72,73^ and 3 were pre-post studies.^74–76^ Four of these studies were conducted among spouses or intimate partners and 1^73^ was conducted among family members. All studies were conducted among intimate partners/family members of Veterans, military service members, or first responders. Four studies were conducted in the US, and 1 was conducted in Canada. Sample sizes ranged from 12-200 (median = 27). All studies had entirely or predominately female samples. Among the 4 studies that reported on race or ethnicity, all had predominately White samples. Three studies required that the patient with PTSD screen positive for probable PTSD using a self-report measure.

Four studies evaluated internet interventions, and 1 study^73^ evaluated an app-based intervention. One RCT^72^ and 1 pre-post study^75^ evaluated VA-CRAFT, an internet intervention that includes safety planning and psychoeducation on PTSD symptoms, self-care, communication skills, and supporting the Veteran in considering treatment options and while engaged in care. The RCT compared the intervention with a minimal contact control (ie, reminders only), and the pre-post study evaluated VA-CRAFT with additional coaching. Two pre-post studies^74,76^ evaluated Couple HOPES, a cognitive behavioral conjoint treatment that includes psychoeducation, communication skills training, and dyadic interventions to address behavioral avoidance, emotional numbing, and cognitions that underlie PTSD and relationship problems. Both studies included coaching. The final study^73^ was an RCT comparing a group with access to PTSD Family Coach, an app that includes psychoeducation, stress management tools, self-assessments, and information on connecting to additional resources, to a psychoeducation-only app.

VA-CRAFT and Couple HOPES were categorized as long interventions, and PTSD Family Coach was completed on a self-guided timeline. Two studies^72,73^ (PTSD Family Coach and the VA-CRAFT RCT) evaluated self-guided interventions with no provider involvement other than reminders or technical support. The remaining 3 studies evaluated interventions that included provider guidance and/or feedback. In 1 of these studies^75^ the provider involvement was primarily synchronous, and the other 2 studies^74,76^ included a combination of synchronous and asynchronous provider involvement. Relevant outcomes assessed included depression symptoms (N = 4), anxiety symptoms (N = 3), caregiver burden (N = 3), and quality of life (N = 3).

Like studies of adults with PTSD, common methodological limitations of RCTs evaluating interventions for family members or caregivers of adults with PTSD included small sample sizes, low treatment adherence, lack of information on the randomization process, high rates of missing data, and lack of intent-to-treat analyses. Pre-post studies were limited by low treatment adherence, lack of accounting for potential confounders in analyses, lack of information on co-interventions, and high levels of missing data.

Table 1 Characteristics of Included Studies

Study | Sample Size; Follow-Up | Study Design | Population; % Probable PTSD | Intervention Characteristics; Modality | Comparator | Outcomes Assessed
PTSD studies
Acosta 2017 ^36^ | N=162; 3 mos | RCT | OEF/OIF/OND Veterans with hazardous alcohol use or substance misuse; 79% | Self-guided iCBT; Internet | TAU | PTSD symptom severity, PTSD treatment response, alcohol use, drug use, quality of life
Allen 2022^37^ | N=49; 3 mos | RCT | Adults; 100% | Guided iCBT; Internet | Waitlist | PTSD symptom severity, PTSD remission, psychological distress, depression, anxiety
Andersson 2021^38^ | N=64; 40 wks | RCT | Adults with prior IPV and current at least moderate mental health problems; 57.1% | Guided iCBT; Internet | Waitlist | PTSD symptom severity, PTSD treatment response, PTSD remission, depression, anxiety, quality of life
Bedard-Gilligan 2022^39^ | N=109; 8 wks | RCT | Adults reporting heavy episodic drinking; 100% | CBT + framing; SMS | Kind attention messages | PTSD symptom severity, alcohol use, anxiety, depression
Bedford 2023^40^ | N=71; 1 mo | RCT | University students and community members; NR | Safety Behavior Elimination for Traumatic Stress; Internet | Modifiable Behavior Intervention | PTSD symptom severity
Bisson 2022^41^ | N=196; 44 wks | RCT | Adults; 100% | Guided trauma-focused iCBT; Internet | In-person trauma-focused CBT | PTSD symptom severity, PTSD remission, depression, anxiety, alcohol use, quality of life, functional impairment
Clausen 2019 ^42^ | N=21; PT | RCT | Male combat Veterans who served since OIF; 60% | Executive function training; Internet | Placebo training | PTSD symptom severity, depression
de Kleine 2019^43^ | N=107; 6 mos | RCT | Adults with a history of IPV; 100% | Self-guided cognitive bias modification training; Internet | Placebo training | PTSD symptom severity, depression
Engel 2015 ^44^ | N=80; 18 wks | RCT | Recently deployed military Service members and Veterans; 100% | Nurse-guided iCBT (DESTRESS); Internet | TAU | PTSD symptom severity, depression, anxiety, somatic symptoms, functioning
Fonzo 2019^45^ | N=84; PT | RCT | Adults; 94% | Cognitive/affective remediation training; Internet | Placebo training | PTSD symptom severity
Gawlytta 2022^46^ | N=25; 12 mos | RCT | Patients after intensive care for sepsis and their spouses; 73.5% | Guided iCBT; Internet | Waitlist | PTSD symptom severity, PTSD treatment response, PTSD remission, psychological distress, health-related quality of life
Hensler 2022^47,77^ | N=179; PT | RCT | Adults; 55.3% | PTSD Coach; App | Waitlist | PTSD symptom severity, PTSD treatment response, PTSD remission, depression, somatic symptoms, functional disability
Hirai 2020^48^ | N=149; 3 mos | RCT | Undergraduate students; 56.3% | Emotion-focused expressive writing intervention; Internet | Fact-focused expressive writing intervention | PTSD symptom severity, PTSD remission
Ivarsson 2014^49^ | N=62; 1 yr | RCT | Adults; 100% | Guided iCBT; Internet | Waitlist | PTSD symptom severity, PTSD treatment response, PTSD remission, depression, anxiety, quality of life
Knaevelsrud 2007^50^ | N=96; 3 mos | RCT | Adults; 70% | Guided iCBT (Interapy); Internet | Waitlist | PTSD symptom severity, depression, anxiety, functioning
Krupnick 2017 ^51^ | N=34; 12 wks | RCT | OIF/OEF/OND Veterans; 100% | Guided trauma-focused iCBT writing intervention (WIRED); Internet | TAU | PTSD symptom severity, depression, alcohol abuse
Kuhn 2017^52^ | N=120; 3 mos | RCT | Adults; 92.5% | PTSD Coach; App | Waitlist | PTSD symptom severity, PTSD treatment response, depression, psychosocial functioning
Lange 2003^53^ | N=184; 6 wks | RCT | Adults; 90% | Guided iCBT (Interapy); Internet | Waitlist | PTSD symptom severity, PTSD treatment response, depression, anxiety, somatic symptoms
Larsen 2019 ^54^ | N=29; 1 mo | RCT | Veterans; 100% | Active emotional working memory training; Internet | Placebo training | PTSD symptom severity, PTSD treatment response, depression, anxiety, stress, negative affect
Lehavot 2021 ^55^ | N=102; 6 mos | RCT | Women Veterans; 100% | Guided iCBT (DESTRESS); Internet | Phone monitoring | PTSD symptom severity, PTSD treatment response
Lewis 2017^56^ | N=42; 3 mos | RCT | Adults; 100% | Guided trauma-focused iCBT; Internet | Waitlist | PTSD symptom severity, depression, anxiety, alcohol use, functional impairment
Littleton 2016^57^ | N=87; 3 mos | RCT | Women college students with rape-related PTSD; 100% | Guided iCBT (From Survivor to Thriver); Internet | Access to psychoeducation website | PTSD symptom severity, depression, anxiety
Litz 2007^58^ | N=45; 4 mos | RCT | Service members; 100% | Guided iCBT (DESTRESS); Internet | Supportive counseling | PTSD symptom severity, depression, anxiety
McCall 2023^70^ | N=163; 8 wks | NRT | Public safety personnel; NR | Guided iCBT; Internet | Wellbeing course | PTSD symptom severity, PTSD treatment response, depression, anxiety, panic symptoms, social phobia symptoms, anger
McGuire 2023 ^59^ | N=48; PT | RCT | Veterans of Iraq or Afghanistan; 100% | Self-guided goal setting intervention (MOVED); Internet | Online assessments only | PTSD symptom severity, moral injury-related distress, quality of life
McLean 2021 ^60^ | N=40; 6 mos | RCT | Active-duty Service members and Veterans; 100% | Prolonged exposure; Internet | In-person present-centered therapy | PTSD symptom severity, depression, functioning
McLean 2022 ^61^ | N=93; 6 wks | RCT | Veterans; 100% | Self-management app (Renew); App | Waitlist | PTSD symptom severity
Miner 2016^62^ | N=49; 1 mo | RCT | Adults; 100% | PTSD Coach; App | Waitlist | PTSD symptom severity, PTSD treatment response
Morabito 2023^63^ | N=51; 1 mo | RCT | University students and community members; 100% | Tonic immobility-focused psychoeducation; Internet | Health education only | PTSD symptom severity
Nieminen 2016^64^ | N=56; PT | RCT | Women with traumatic childbirth; 100% | Guided trauma-focused iCBT; Internet | Waitlist | PTSD symptom severity, depression, anxiety, quality of life
Possemato 2011 ^65^ | N=31; PT | RCT | Veteran primary care patients; 48.4% | Self-guided written emotional disclosure; Internet | Time management narratives | PTSD symptom severity, quality of life
Possemato 2016 ^66^ | N=20; PT | RCT | Veteran primary care patients; 100% | Clinician-supported PTSD Coach; App | Self-managed PTSD Coach | PTSD symptom severity, PTSD treatment response, depression, quality of life
Possemato 2019 ^67^ | N=30; 12 wks | RCT | Veteran primary care patients with hazardous alcohol use; 60% | Peer-supported iCBT; Internet | Self-managed iCBT | PTSD symptom severity, alcohol use, quality of life
Spence 2011^68^ | N=44; PT | RCT | Adults; 100% | Guided iCBT; Internet | Waitlist | PTSD symptom severity, PTSD remission, depression, anxiety, psychosocial functioning
Spence 2014^69^ | N=125; 3 mos | RCT | Adults; 86% | Guided iCBT with exposure; Internet | iCBT without exposure | PTSD symptom severity, PTSD remission, depression, anxiety
Wiltsey Stirman 2021^71^ | N=51; PT | Cohort | Adults; 100% | Cognitive Processing Therapy; Internet | Talkspace as usual (propensity score-matched) | PTSD symptom severity, PTSD treatment response
Family member/caregiver studies
Crenshaw 2023^74^ | N=27; 1 mo | Pre-post | Romantic partners of military members, Veterans, and first responders with PTSD; NA | Guided cognitive-behavioral conjoint treatment (Couple HOPES); Internet | NA | Depression, anxiety, anger, alcohol misuse, quality of life, functioning
Erbes 2020 ^72^ | N=46; PT | RCT | Spouses or intimate partners of Veterans with PTSD; NA | Self-guided family outreach training (VA-CRAFT); Internet | NA | Caregiver burden, general mental health symptoms and distress, quality of life
Kuhn 2023 ^75^ | N=12; PT | Pre-post | Spouses and intimate partners of Veterans with PTSD; NA | Coach-guided family outreach training (VA-CRAFT); Internet | NA | Depression, anxiety, caregiver burden
Morland 2023 ^76^ | N=15; PT | Pre-post | Romantic partners of Veterans with PTSD; NA | Guided cognitive-behavioral conjoint treatment (Couple HOPES); Internet | NA | Depression, quality of life
van Stolk-Cooke 2023 ^73^ | N=200; PT | RCT | Adult family members of veterans with PTSD; NA | PTSD Family Coach; App | Psychoeducation-only app | Caregiver burden, stress, depression, anxiety, self-efficacy

Notes. Bold font indicates studies conducted among Veterans and/or military service members.

Abbreviations. CBT=cognitive behavioral therapy; DESTRESS=Delivery of Self Training and Education for Stressful Situations; HOPES=Helping Overcome PTSD and Enhance Satisfaction; iCBT=internet-based cognitive behavioral therapy; IPV=interpersonal violence; MOVED= Moral Elevation Online Intervention for Veterans Experiencing Distress Related to PTSD and Moral Injury; NA=not applicable; NR=not reported; NRT=non-randomized trial; OEF=Operation Enduring Freedom; OIF=Operation Iraqi Freedom; OND=Operation New Dawn; PT=posttreatment; PTSD=posttraumatic stress disorder; RCT=randomized controlled trial; SMS=short messaging service; TAU=treatment as usual; VA-CRAFT=Veterans Affairs—Community Reinforcement and Family Training; WIRED=Warriors Internet Recovery & Education.

## KEY QUESTION 1 INTERNET AND MOBILE INTERVENTIONS FOR ADULTS WITH PTSD

### PTSD Outcomes

Thirty-two studies^36–40,42–44,46–58,60–64,66–71^ assessed the effectiveness of internet or mobile interventions on PTSD symptoms immediately post-treatment (31 RCTs, 1 cohort; total N = 2,237). Of these, 21 studies were conducted in civilian populations (total N = 1,655) and 11 in military populations (Veterans or active-duty service members; total N = 582). Among civilians, internet or mobile interventions may result in moderate post-treatment improvements in PTSD symptom severity (SMD = 0.42, 95% CI [0.18, 0.67]; number of effect sizes [N_es_] = 34). However, intervention effects among military populations may be small to negligible (SMD = 0.10, 95% CI [−0.11, 0.30]; N_es_ = 12). For both populations, we have low confidence in findings (low SOE) because of study methodological limitations and moderate inconsistency in effects across studies.

Eighteen RCTs^36,39–41,43,44,48,51,54–58,60,63,65,67,69^ reported PTSD symptom severity outcomes at short-term follow up (1-3 months; total N = 1,228). Nine of these studies were carried out in military populations (total N = 470). Among civilians, overall improvement in PTSD symptom severity was smaller and no longer statistically significant compared with immediately post-treatment (SMD = 0.24, 95% CI [−0.18, 0.65]; N_es_ = 20). Intervention effects remained small to negligible for Veterans or active-duty service members (SMD = 0.10, 95% CI [−0.13, 0.33]; N_es_ = 11). Five RCTs^41,43,55,58,60^ (total N = 388) also reported outcomes at long-term follow up (4 to 11 months), and when pooled, no intervention effect on PTSD symptom severity was apparent (SMD = −0.06, 95% CI [−0.45, 0.33]; N_es_ = 6). This result includes evidence from both civilian and military populations because of the small number of studies. Based on this evidence, internet or mobile interventions may have no effect on PTSD symptom severity among civilian or military populations at 1-3 months or 4+ months after treatment. We have low confidence in these findings based on study methodological limitations, imprecision, and moderate inconsistency.

Comparatively few trials reported on the proportion of participants with clinically meaningful PTSD symptom improvement, reliable change, or recovery/remission after the intervention (ranging from 6 to 13 trials per outcome). Results could be disaggregated by military or civilian status only for clinically meaningful PTSD symptom improvement. Based on available evidence, internet and mobile interventions may increase odds of clinically meaningful PTSD symptom improvement post-treatment among civilian but not military populations. Interventions may improve odds of recovery, remission, or no longer meeting diagnostic criteria and reliable symptom improvement or change, but it is unclear whether this benefit differs between civilian and military populations. Our confidence in these findings is low based on study methodological limitations, imprecision, and substantial inconsistency.

Compared with control participants, civilian participants receiving the intervention had greater odds of clinically meaningful PTSD symptom improvement post-treatment (OR = 1.97, 95% CI [0.80, 4.83]; k = 6, N_es_ =7), though this difference was nonsignificant. Odds of clinically meaningful improvement also favored the intervention among Veterans or active-duty service members (OR = 1.36, 95% CI [0.52, 3.58]; k = 4, N_es_ =7), but the difference was much smaller in magnitude compared with civilians and also nonsignificant. Not accounting for military or civilian status, participants who received the intervention also had significantly greater odds of recovery, remission, or no longer meeting diagnostic criteria (OR = 2.27, 95% CI [1.24, 4.17]; k = 13, N_es_ = 13) and reliable symptom improvement or change (OR = 3.92, 95% CI [1.46, 10.54]; k = 6, N_es_ = 8).

Figure 1 Differences in PTSD Symptoms Immediately Post-Treatment

Abbreviations. CAPS=Clinician-Administered PTSD Scale; CAPS-5=Clinician-Administered PTSD Scale for DSM-5; CI=confidence interval; IES=Impact of Events Scale; IES-R=Impact of Events Scale – Revised; PCL-5=PTSD Checklist for DSM-V; PCL-C=PTSD Checklist – Civilian version; PCL-M=PTSD Checklist – Military version; PCL-S=PTSD Checklist – Specific version; PDS=Posttraumatic Stress Diagnostic Scale; PI=prediction interval; PSS-I=Posttraumatic Stress Symptom Scale – Interview version; PSS-SR=Posttraumatic Symptom Scale – Self-report; SMD=standardized mean difference; TES=Traumatic Event Scale.

### Depression Outcomes

Intervention effects on depression symptoms followed a similar pattern to effects on PTSD symptoms. Twenty trials^37–39,42–44,47,49–54,56–58,64,66,69,70^ evaluated the effectiveness of internet or mobile interventions on depression symptoms immediately post-treatment (19 RCTs, 1 NRT; total N = 1,458). Of these, 6 trials were conducted in military populations (total N = 171). Based on this evidence, internet and mobile interventions may result in small post-treatment improvements in depression symptoms among civilians (SMD = 0.28, 95% CI [0.04, 0.53]; N_es_ = 17), but may not result in post-treatment symptom improvements among Veterans or active-duty service members (SMD = −0.03, 95% CI [−0.36, 0.30]; N_es_ = 6). Based on 11 studies,^39,41,43,44,51,54,56–58,69^ internet and mobile interventions may have no effect on depression symptom severity 1-3 months after treatment among both civilians (SMD = 0.07, 95% CI [−0.41, 0.55]; k = 7, N_es_ = 7) and military populations (SMD = −0.11, 95% CI [−0.41, 0.20]; k = 4, N_es_ = 5). We have low confidence in findings on depression outcomes due to study methodological limitations and inconsistency in effects across studies.

### Variation in Intervention Effects

Results of subgroup analyses based on intervention and methodological characteristics are shown in Table 2. These results are informative about potential sources of variation in intervention effects on PTSD and depression symptom severity but should be interpreted with caution because they are based on all available evidence regardless of time point and military or civilian status. Results of moderation analyses were not considered in overall conclusions about intervention effectiveness or strength of evidence judgments.

Subgroup analyses suggest that a potential source of variability in intervention effectiveness is delivery modality. As shown in Table 2, comparable-magnitude improvements in PTSD symptoms were observed for both internet interventions and mobile interventions. In contrast, the overall effect for SMS-based interventions was negligible or potentially negative based on results from a single trial of 2 independent cohorts.^39^ Another apparent source of variability in effects is the level of facilitation. Interventions that used direct facilitation appeared to have the largest effect on PTSD symptoms. Interventions with guidance or feedback only had a somewhat smaller overall effect, while the pooled effect estimate for interventions that offered no facilitation (ie, reminders or technical support only) was small to negligible. Intervention effects did not appear to differ based on intervention duration (brief, moderate, long, or self-guided timeline) or whether the intervention incorporated written exposure elements.

Regarding study methodological characteristics, observed intervention effects were similar regardless of whether a clinician-administered or self-reported outcome measure was used (Table 2). Observed effects strongly favored interventions when compared with a completely inactive condition like waitlist control. Effects were considerably smaller against another active treatment condition (excluding in-person therapy). As noted above, 2 studies^41,60^ compared an internet treatment to an evidence-based in-person therapy. One of these was a large RCT^41^ (N = 139) that compared iCBT to face-to-face CBT among civilians in the United Kingdom (UK) National Health Services, finding that the internet intervention was non-inferior on PTSD outcomes at post-treatment.^41^ The second study^60^ was a small feasibility study (N = 40) on treatment-seeking military service members and Veterans that found no difference in post-treatment PTSD symptoms between web-based PE and face-to-face present-centered therapy.

Table 2 Subgroup Analysis Results for PTSD and Depression Symptom Severity

| PTSD; SMD [95% CI] | Depression; SMD [95% CI]
Modality
Internet | 0.34 [0.14, 0.54] (k = 28, N_es_ = 74) | 0.22 [0.02, 0.42] (k = 18, N_es_ = 32)
App | 0.31 [−0.06, 0.68] (k = 5, N_es_ = 5) | 0.33 [−0.78, 1.44] (k = 2, N_es_ = 2)
SMS/text message | −0.12 [−9.88, 9.64] (k = 1, N_es_ = 4)^a^ | −0.24 [−8.99, 8.50] (k = 1, N_es_ = 4)^a^
Facilitator Involvement^b^
Direct facilitation | 0.60 [−0.12, 1.32] (k = 6, N_es_ = 15) | 0.31 [−0.58, 1.20] (k = 4, N_es_ = 8)
Minimal support | 0.35 [0.02, 0.67] (k = 14, N_es_ = 30) | 0.26 [−0.03, 0.55] (k = 10, N_es_ = 15)
None (reminders or technical support only) | 0.18 [−0.04, 0.40] (k = 13, N_es_ = 37)^a^ | 0.05 [−0.35, 0.44] (k = 7, N_es_ = 15)^a^
Duration
Brief | 0.33 [−0.05, 0.71] (k = 5, N_es_ = 20) | 0.27 [0.01, 0.54] (k = 1, N_es_ = 3)
Moderate | 0.37 [−0.44, 1.17] (k = 5, N_es_ = 12)^a^ | 0.19 [−0.76, 1.13] (k = 4, N_es_ = 8)^a^
Long | 0.29 [0.04, 0.55] (k = 20, N_es_ = 47) | 0.14 [−0.06, 0.35] (k = 14, N_es_ = 25)
Self-guided timeline | 0.29 [−0.14, 0.72] (k = 4, N_es_ = 4) | 0.33 [−0.78, 1.44] (k = 2, N_es_ = 2)
Written Exposure
CBT + written exposure | 0.39 [0.05, 0.73] (k = 13, N_es_ = 38) | 0.26 [−0.09, 0.62] (k = 8, N_es_ = 12)
CBT only | 0.28 [0.06, 0.51] (k = 19, N_es_ = 41)^a^ | 0.18 [−0.11, 0.46] (k = 11, N_es_ = 23)^a^
Outcome Assessment
Clinician-administered | 0.24 [−0.40, 0.88] (k = 6, N_es_ = 12) | —
Self-reported | 0.31 [0.13, 0.49] (k = 32, N_es_ = 71)^a^ | —
Comparison Condition
Active Control | 0.18 [−0.13, 0.50] (k = 11, N_es_ = 33)^a^ | 0.03 [−0.47, 0.53] (k = 6, N_es_ = 14)^a^
In-person therapy | −0.48 [−5.67, 4.71] (k = 2, N_es_ = 7) | −0.12 [−0.52, 0.29] (k = 1, N_es_ = 2)
Minimal contact | 0.15 [−0.53, 0.83] (k = 1, N_es_ = 3) | —
No exposure | −0.24 [−0.26, −0.22] (k = 1, N_es_ = 4) | 0.05 [0.03, 0.06] (k = 1, N_es_ = 2)
No guidance | 0.30 [−2.96, 3.57] (k = 2, N_es_ = 3) | −0.10 [−0.97, 0.78] (k = 1, N_es_ = 1)^c^
Psychoeducation | 0.58 [0.44, 0.72] (k = 1, N_es_ = 2) | −0.27 [−0.50, −0.04] (k = 1, N_es_ = 2)
Treatment as usual | 0.15 [−0.61, 0.90] (k = 3, N_es_ = 8) | −0.16 [−1.18, 0.86] (k = 2, N_es_ = 5)
Waitlist | 0.63 [0.36, 0.88] (k = 13, N_es_ = 23) | 0.50 [0.27, 0.72] (k = 9, N_es_ = 12)

Notes.

a Bedard-Gilligan 2022 reports results for 2 independent waves.

b McLean 2022 (N = 93) combined 2 active conditions into a treatment group and is not included in subgroup analysis.

c Reported SMD (d) and estimated 95% CI from single trial with no guidance comparison condition (Possemato 2016).

Abbreviations. N_es_=number of effect sizes included in analysis; SMD=standardized mean difference (g).

### Other Outcomes

Other outcomes of interest reported on by more than 1 study included generalized anxiety symptom severity, alcohol use, psychological distress, somatic symptoms, quality of life, and functioning. We did not conduct a meta-analysis or assess strength of evidence for these outcomes, but, overall, findings were mixed across studies.

Fifteen studies^37–39,41,44,49,50,54,56–58,64,68–70^ reported on anxiety symptom severity (Table 3). Of these, 12 studies were conducted among civilian populations and 3 with Veteran or military populations. No studies were conducted exclusively among Veterans receiving VHA care. Among the civilian studies, 1 trial^41^ that compared iCBT to face-to-face CBT found that improvements in generalized anxiety symptoms in the iCBT group were non-inferior to the face-to-face CBT group. Four other civilian trials that compared iCBT to a waitlist condition found significant improvements on anxiety severity at post-treatment favoring iCBT.^49,50,56,68^ The 3 trials conducted with Veterans and/or military service members found non-significant improvements on anxiety severity at posttreatment relative to an active comparator.^44,54,58^

Five RCTs^36,39,41,51,56,67^ reported on alcohol use/misuse outcomes (Table 4). Three of these studies^36,39,67^ evaluated interventions that targeted alcohol misuse in addition to PTSD and required that participants endorse alcohol misuse. Three studies were conducted among Veterans receiving VHA care; the remaining 2 studies were conducted among civilians. Outcomes varied and results were mixed across trials and were not consistent across comparator types.

Two RCTs^37,46^ conducted among civilians reported on psychological distress; neither found that CBT-based internet interventions for PTSD improved psychological distress symptoms at post-treatment compared to waitlist. Three RCTs reported on somatic symptoms; 2 evaluated internet interventions^44,53^ and 1 evaluated an app-based intervention.^47^ One RCT^53^ conducted among civilians comparing an internet intervention to waitlist found a large effect at post-treatment, but the study was rated high risk of bias. The other 2 studies, including 1 study^44^ conducted among Veterans and military service members, did not find evidence of an effect on somatic symptom severity.

Ten RCTs^36,38,41,46,49,59,64–67^ reported on quality-of-life outcomes (Table 5). Five of these studies were conducted among Veterans receiving VHA care; the remaining 5 studies were conducted among civilians. Results were mixed across trials and were not consistent across comparator types.

Eight RCTs^41,44,47,50,52,56,60,68^ reported on outcomes related to functioning (Table 6). Two studies were conducted among Veterans and military service members; the remaining studies were conducted among civilians. Results were mixed across trials and were not consistent across comparator types. Five trials conducted among civilians reported some positive effect of internet or mobile interventions for PTSD on functioning, but neither trial conducted among Veterans and military service members found a significant effect of the intervention on functioning outcomes.

Table 3 Effects of Internet and Mobile Interventions for PTSD on Anxiety Symptom Severity

Study; Follow-Up | N | Intervention and Comparator | Anxiety Outcomes
Internet interventions
Allen 2022^37^; PT | 40 | iCBT compared to waitlist | No significant difference between groups in change in GAD-7 score from pre- to post-treatment (F2, 73.49 = 0.47, p = 0.63); between group effect size (g [95% CI] = 0.26 [−.47, .98]).
Andersson 2021^38^; PT | 64 | iCBT compared to waitlist | No significant group differences at PT: iCBT group mean (SD) = 15.62 (11.33); waitlist group mean (SD) = 20.70 (12.5).
Bisson 2022^41^; 44 weeks | 160 | iCBT compared to in-person CBT | iCBT was non-inferior to face-to-face CBT at 8 weeks (d [95% CI] = 0.10 [−∞, 0.41]) but inconclusive at 44 weeks (d [95% CI] = 0.47 [−∞, 0.78]).
Engel 2015 ^44^; 12 weeks | 58 | iCBT compared to TAU | No significant difference between groups in change in PHQ anxiety score at PT, 6-week, or 12-week follow-up.
Ivarsson 2014^49^; PT | 62 | iCBT compared to waitlist | Significant time by treatment interaction effects for BAI score favoring iCBT group at PT: Cohen’s d [95% CI] = 0.60 [0.04, 1.13].
Knaevelsrud 2007^50^; PT | 95 | iCBT compared to waitlist | Significant time by treatment interaction effects for BSI anxiety score favoring iCBT group at PT: F = 10.73; p < .001.
Larsen 2019 ^54^; 1 month | 29 | Active emotional working memory training compared to control training | No significant difference between groups in change in DASS anxiety score from pre- to post-treatment or 1-month follow-up.
Lewis 2017^56^; 1 month | 42 | iCBT compared to waitlist | At PT there was a significant difference in BAI score between groups favoring the iCBT group (between-group mean difference [95% CI] = 13.40 [−19.91, −6.35]. These differences remained at 1 month.
Littleton 2016^57^; PT | 51 | iCBT compared to psychoeducational website | No significant difference between groups in change in FDAS score from pre- to post-treatment (b = 8.62, SE = 5.71, p = 0.139, d = 0.46).
Litz 2007 ^58^; 4 months | 31 | iCBT compared to supportive counseling | No significant differences between groups in BAI score in ITT analyses; between group effect sizes (d) = 0.40 at PT, d = 0.54 at 3 months, d = 1.01 at 6 mos.
McCall 2023^70^; PT | 150 | iCBT compared to well-being course | No significant difference between groups in change in GAD-7 score (χ^2^ = 2.9, p = .166) from pre- to post-treatment.
Nieminen 2016^64^; PT | 56 | iCBT compared to waitlist | No between group effect for BAI score (d [95% CI] = .18 [−0.34, .071])
Spence 2011^68^; PT | 42 | iCBT compared to waitlist | iCBT group had significantly lower PT GAD-7 scores than the control group at PT (F1,39 = 4.62, p < .04), with a moderate between-group effect (d [95% CI] = 0.55 [−1.03, 3.00].
Spence 2014^69^; 3 months | 125 | iCBT with exposure compared to iCBT without exposure | No evidence of significant differential changes from baseline to PT or 3 months between groups in GAD-7 scores (F2, 123 = 0.8, p = 0.451); PT between-group effect size (d [95% CI] = 0.24 [−0.11, 0.59], 3-month between-group effect size (d [95% CI] = −0.04 [−0.39, 0.31])
SMS interventions
Bedard-Gilligan 2022^39^; 1 month | 109 | CBT-based SMS intervention compared to kind attention messages | Wave 1: Change in DASS anxiety score not significantly different between groups at PT (B[SE] = 0.16 [0.17]) and 1 month (B[SE] = 0.10 [0.31]); Wave 2: Reduction was greater in the CBT group at PT (B[SE] = −0.61 [0.20], p < .05) but not at 1 month (B[SE] = −0.68 [0.36]).

Notes. Bold font indicates studies conducted among Veterans and/or military service members.

Abbreviations. BAI=Beck Anxiety Inventory; BSI=Brief Symptom Inventory; CI=confidence interval; DASS=Depression Anxiety Stress Scale; FDAS=Four Dimensional Anxiety Scale; GAD-7=Generalized Anxiety Disorder-7; iCBT=internet-based cognitive behavioral therapy; ITT=intent-to-treat; PDSS-SR=Panic Disorder Severity Scale Self-Report; PHQ=Patient Health Questionnaire; PT=post-treatment; SE=standard error; SIAS-6=Social Interaction Anxiety Scale; SMS=short messaging service; SPS-6=Social Phobia Scale; TAU=treatment as usual.

Table 4 Effects of Internet and Mobile Interventions for PTSD on Alcohol Use Outcomes

Study; Follow-Up | N | Intervention and Comparator | Alcohol Use Outcomes
Internet interventions
Acosta 2017 ^36^; 3 months | 162 | iCBT compared to TAU | iCBT group reported significantly greater declines in % heavy drinking days vs TAU at PT on the TLFB (difference [±SE] = −1.80 ± 0.79; p < 0.05), with effects maintained at 3 months (difference [±SE] = 1.89 ± 1.33). Differences between groups in % drinking days were non-significant at PT and 3 months.
Bisson 2022^41^; 44 weeks | 160 | iCBT compared to in-person CBT | On the AUDIT, iCBT was non-inferior to in-person CBT at 8 weeks (d [95% CI] = 0.15 [−∞, 0.32]) and 44 weeks (d [95% CI] = 0.13 [−∞, 0.35]).
Krupnick 2017 ^51^; 12 weeks | 31 | iCBT compared to TAU | No significant time by treatment interaction effects for AUDIT score. AUDIT scores increased for both groups.
Lewis 2017^56^; 1 month | 42 | iCBT compared to waitlist | No significant differences in AUDIT scores between groups at PT (between-group mean difference [95% CI] = 2.13 [−6.02, 1.63]) or at 1 month.
Possemato 2019 ^67^; 12 weeks | 20 | Peer-supported iCBT compared to self-managed iCBT | No between group differences were observed using the TLFB at PT for drinking days (d [95% CI] = .13 [−.59, .84] or heavy drinking days (d [95% CI] = .17 [−.55, .89]).
SMS interventions
Bedard-Gilligan 2022^39^; 1 month | 109 | CBT-based SMS intervention compared to kind attention messages | Wave 1: Change in drinks per week^a^ was not significantly different between groups at PT (B [SE] = 0.11 [0.21]) and 1 month (B [SE] = −0.01 [0.40]). Among participants with at least 1 heavy drinking episode, reductions in HED^b^ were greater for the treatment group at PT (B [SE] = −0.60 [1.29]) and 1 month (B [SE] = −0.67 [1.28]).; Wave 2: Change in drinks per week was not significantly different between groups at PT (B [SE] = −0.28 [0.16]) and 1 month (B [SE]) = −0.03 [0.25]). Changes in HED were not significantly different between groups at PT (B [SE] = −2.34 [1.40]) and 1 month (B [SE] = −2.09 [1.39]).

Notes. Bold font indicates studies conducted among Veterans and/or military service members.

a Drinks per week assessed using the Daily Drinking Questionnaire;

b Heavy episodic drinking assessed using the National Institute on Alcohol Abuse and Alcoholism Recommended Alcohol Questions.

Abbreviations. AUDIT= Alcohol Use Disorders Identification Test; CBT=cognitive behavioral therapy; aCI=confidence interval; HED=heavy episodic drinking; iCBT=internet-based cognitive behavioral therapy; PT=post-treatment; SE=standard error; SMS=short messaging service; TAU=treatment as usual; TLFB=Timeline Follow Back.

Table 5 Effects of Internet and Mobile Interventions for PTSD on Quality of Life

Study; Follow-Up | N | Intervention and Comparator | Quality of Life Outcomes
Internet interventions
Acosta 2017 ^36^; 3 months | 162 | iCBT compared to TAU | There was no significant effect of treatment on WHOQOL-BREF scores over time.
Andersson 2021^38^; PT | 64 | iCBT compared to waitlist | No significant group differences in QOLI scores at PT: iCBT group mean (SD) = 0.56 (1.92); waitlist group mean (SD) = 0.07 (1.57).
Bisson 2022^41^; 44 weeks | 160 | iCBT compared to in-person CBT | On the EQ-5D-5L, iCBT was non-inferior to in-person CBT at 8 weeks (d [95% CI] = 0.09 [−∞, 0.33]) and borderline non-inferior at 44 weeks (d [95% CI] = 0.22 [−∞, 0.50]).
Gawlytta 2022^46^; PT | 34 | iCBT compared to waitlist | No association between score changes on the EQ-5D-5L and iCBT with effect size (95% CI) = 0.25 (−0.42, 0.93).
Ivarsson 2014^49^; PT | 62 | iCBT compared to waitlist | Significant time by treatment interaction effects on the QOLI favoring iCBT group at PT (Cohen’s d [95% CI] = 0.53 [−0.02, 1.06]).
McGuire 2023 ^59^; PT | 36 | Internet goal setting intervention compared to minimal contact | At PT, the treatment group reported a medium, significant increase in the physical (Cohen’s d = 0.71) and psychological domains (Cohen’s d = 0.74) of the WHOQOL-BREF but no changes in the social or environmental domains. Participants in the control group reported no significant changes in any of the domains.
Nieminen 2016^64^; PT | 56 | iCBT compared to waitlist | No between group effect at PT for QOLI (d [95% CI] = −.07 [−.59, .45]) or EQ-5D-5L (d [95% CI] = −.07 [−.59, .48]).
Possemato 2011 ^65^; PT | 26 | iCBT (written emotional disclosure) compared to time management narratives | On the SF-12, iCBT group did not have significantly larger increases in physical health-related QOL (p = 0.96) or mental health-related QOL (p = 0.62) at PT compared to control participants.
Possemato 2019 ^67^; PT | 20 | Peer-supported iCBT compared to self-managed iCBT | No between-group differences were observed at PT on the WHOQOL-BREF for psychological QOL (d [95% CI] = .34 [−.39, 1.06] or social QOL (d [95% CI] = .13 [−.59, .84]).
App-based interventions
Possemato 2016^66^; PT | 20 | Clinician-supported PTSD Coach compared to self-managed PTSD Coach | Group by time effect sizes for changes in psychological QOL and social QOL on the WHOQOL-BREF were medium (d = .59) and large (d = 1.46), respectively.

Notes. Bold font indicates studies conducted among Veterans and/or military service members.

Abbreviations. CI=confidence interval; EQ-5D-5L= EuroQol 5-dimension 5-level; iCBT=internet-based cognitive behavioral therapy; PT=post-treatment; PTSD=posttraumatic stress disorder; QOL=quality of life; QOLI=Quality of Life Inventory; SF-12=12-Item Short Form Health Survey; TAU=treatment as usual; WHOQOL-BREF=World Health Organization Quality of Life – Brief.

Table 6 Effects of Internet and Mobile Interventions for PTSD on Functioning

Study; Follow-Up | N | Intervention and Comparator | Functioning Outcomes
Internet interventions
Bisson 2022^41^; 44 weeks | 160 | iCBT compared to in-person CBT | On the WSAS, iCBT was non-inferior to in-person CBT at 8 weeks (d [95% CI] = −0.14 [−∞, 0.13]) but inconclusive at 44 weeks (d [95% CI] = 0.24 [−∞, 0.53]).
Engel 2015 ^44^; 12 weeks | 58 | iCBT compared to TAU | Group by time interaction on the SF-36 was non-significant at all time points.
Knaevelsrud 2007^50^; PT | 95 | iCBT compared to waitlist | On the SF-12, group by time pre-post effect size change favored the iCBT group for mental health functioning (F=5.95, p < .05), but the effect was not significant for physical health functioning.
Lewis 2017^56^; 1 month | 42 | iCBT compared to waitlist | At PT, there was a significant difference between groups on the SDS (between-group mean difference [95% CI] = 9.36 [−13.56, −3.93]). These differences remained at 1 month.
McLean 2021 ^60^; 6 months | 25 | Web prolonged exposure compared to in-person present-centered therapy | Group by time interaction was not significant for either the mental or physical component scores of the VR-12.
Spence 2011^68^; PT | 42 | iCBT compared to waitlist | iCBT group did not have significantly lower PT SDS scores than waitlist (d [95% CI] = 0.62 [−2.38, 4.85]).
App-based interventions
Kuhn 2017^52^; PT | 120 | PTSD Coach compared to waitlist | PTSD Coach condition had greater improvement on the B-IPF than waitlist (F[1, 117] = 7.63, p = .007, d = 0.51).
Hensler 2022^47^; PT | 179 | PTSD Coach compared to waitlist | PTSD Coach condition had greater improvement on the WHODAS than waitlist (B = −5.39, SE = 2.49, 95% CI = −10.28, −0.50, t(301.83) = −2.17, p = 0.031; Cohen’s d = −0.27).

Notes. Bold font indicates studies conducted among Veterans and/or military service members.

Abbreviations. B-IPF=Brief Inventory of Psychosocial Functioning; CBT=cognitive behavioral therapy; CI=confidence interval; iCBT=internet-based cognitive behavioral therapy; PT=post-treatment; SDS=Sheehan Disability Scale; SF-12=12-Item Short Form Health Survey; SF-36= 36-Item Short Form Health Survey; TAU=treatment as usual; VR-12=Veteran’s RAND 12-item Health Survey; WHODAS=World Health Organization Disability Assessment Schedule; WSAS=Work and Social Adjustment Scale.

## KEY QUESTION 2 INTERNET AND MOBILE INTERVENTIONS FOR FAMILY MEMBERS AND CAREGIVERS OF ADULTS WITH PTSD

Five studies^72–76^ were included that evaluated an intervention for family members or caregivers of adults with PTSD (2 RCTs, 3 pre-post studies; total N = 300). Three different family interventions were identified across the included studies: 2 internet interventions (VA-CRAFT, Couple HOPES) and 1 mobile intervention (PTSD Family Coach). The 2 RCTs were conducted on VA-CRAFT (comparator was waitlist control) and PTSD Family Coach (comparator was psychoeducation app). Four of the studies were conducted in the US and 1 in Canada; all the trials were conducted among intimate partners/family members of Veterans, military Service members, or first responders.

Studies reported on a variety of outcome measures. Four outcomes that were reported by at least 2 studies were included in our synthesis: caregiver burden, depression, anxiety, and quality of life. Across treatments and outcomes, there appeared to be little to no benefit of interventions on most outcomes. Most studies had high risk of bias and the strength of evidence across outcomes was low.

### Caregiver Burden

It is unclear whether internet and mobile interventions reduce caregiver burden symptoms for family members of adults with PTSD. Our confidence in this finding is low based on study methodological limitations and inconsistent findings across studies. Three studies^72,73,75^ (2 RCTs and 1 pre-post; N = 258) assessed the effectiveness of an internet (2 studies) or mobile intervention (1 study) on caregiver burden symptoms at post-treatment (Table 7). Two studies^72,75^ evaluated the same internet intervention (VA-CRAFT). Caregiver burden symptoms improved in the first study relative to a waitlist control group (RCT, N = 46),^72^ but no improvements were detected in the second study (pre-post; N = 12).^75^ One RCT^73^ (N = 200) that evaluated an app-based intervention did not detect any improvement in caregiver burden relative to an education-only app comparator.

Table 7 Effects of Internet and Mobile Interventions for Family Members of Adults with PTSD on Caregiver Burden

Study; Follow-Up | N | Intervention and Comparator | Caregiver Burden Outcomes
Internet interventions
Erbes 2020^72^; PT | 46 | VA-CRAFT compared to waitlist | Large treatment effect for intervention group at PT (F[1, 12] = 9.31, eta^2^ = 0.20, p < .01).
Kuhn 2023^75^; PT | 12 | Guided VA-CRAFT (pre-post) | No significant change in CBS scores from baseline to PT (d = −0.02, p = .942).
App-based interventions
Van Stolk-Cooke 2023^73^; PT | 200 | PTSD Family Coach app compared to psychoeducation-only app | No significant treatment by time interaction for CBS scores at PT (d [95% CI] = 0.1 [−0.2, 0.4], p = .45).

Abbreviations. CBS=Caregiver Burden Scale; CI=confidence interval; PT=posttreatment; PTSD=posttraumatic stress disorder.

### Depression

Internet and app-based interventions for family members of adults with PTSD may have no effect on depression symptoms. Though findings were consistent across studies, our confidence in this finding is low based on high risk of bias of all studies. Four studies (1 RCT and 3 pre-post; N = 254) assessed the effectiveness of an internet (3 studies)^74–76^ or mobile intervention (1 study)^73^ on depression symptoms at post-treatment (Table 8). Across studies, there were no improvements detected on depressive symptoms at post-treatment.

Table 8 Effects of Internet and Mobile Interventions for Family Members of Adults with PTSD on Depression

Study; Follow-Up | N | Intervention and Comparator | Depression Outcomes
Internet interventions
Crenshaw 2023^74^; 1 month | 27 | Couple HOPES (pre-post) | No improvement on PHQ-9 from baseline to PT (g [95% CI] = 0.42 [−0.02, 0.87]) or baseline to 1-month (g [95% CI] = 0.38 [−0.41, 1.18]).
Kuhn 2023^75^; PT | 12 | Guided VA-CRAFT (pre-post) | No change in PHQ-9 scores from baseline to PT (d = 0.32, p = .364).
Morland 2023^76^; PT | 15 | Couple HOPES (pre-post) | No change in PHQ-9 scores from baseline to PT (g = −0.20, p = .142).
App-based interventions
Van Stolk-Cooke 2023^73^; PT | 200 | PTSD Family Coach app compared to psychoeducation-only app | No significant treatment by time interaction for PHQ-8 scores at PT (d [95% CI] = −0.0 [−0.3, 0.3], p = .93).

Abbreviations. CI=confidence interval; iCBT=internet-based cognitive behavioral therapy; PHQ-8=8-item Patient Health Questionnaire; PHQ-9=9-item Patient Health Questionnaire; PT=posttreatment; PTSD=posttraumatic stress disorder.

### Anxiety

Internet and mobile interventions for family members of adults with PTSD may have no effect on anxiety symptom severity. Though findings were consistent across studies, our confidence in this finding is low based on high risk of bias of all studies. Three studies (1 RCT and 2 pre-post; N = 239) assessed the effectiveness of internet (2 studies)^74,75^ or mobile interventions (1 study)^73^ on anxiety symptoms (Table 9). No significant benefits were detected across treatments.

Table 9 Effects of Internet and Mobile Interventions for Family Members of Adults with PTSD on Anxiety

Study; Follow-Up | N | Intervention and Comparator | Anxiety Outcomes
Internet interventions
Crenshaw 2023^74^; 1 month | 27 | Couple HOPES (pre-post) | No improvement on GAD-7 from baseline to PT (g [95% CI] = 0.17 [−0.19, 0.51]) or baseline to 1-month follow-up (g [95% CI] = 0.52 [−0.06, 1.10]).
Kuhn 2023^75^; PT | 12 | Guided VA-CRAFT (pre-post) | No change in PROMIS-SF anxiety scores from baseline to PT (d = 0.08, p = .822).
App-based interventions
Van Stolk-Cooke 2023^73^; PT | 200 | PTSD Family Coach app compared to psychoeducation-only app | No significant treatment by time interaction for GAD-7 scores at PT (d [95% CI] = −0.1 [−0.4, 0.2], p = .55).

Abbreviations. CI=confidence interval; GAD-7=Generalized Anxiety Disorder-7; iCBT=internet-based cognitive behavioral therapy; PT=posttreatment; PROMIS-SF=Patient-Reported Outcomes Measurement Information System – Short Form; PTSD=posttraumatic stress disorder.

### Quality of Life

It is unclear whether internet interventions for family members of adults with PTSD improve quality of life. Our confidence in this finding is low based on study methodological limitations and inconsistent findings across studies. Three studies^72,74,76^ (1 RCT and 2 pre-post; N = 88) assessed the effectiveness of internet-based interventions on quality of life (Table 10). One pre-post study^74^ (Couple HOPES) detected improvement in quality of life from baseline to PT, but not from baseline to 1-month follow-up. No significant benefits were detected in the 2 other trials.^72,76^

Table 10 Effects of Internet and Mobile Interventions for Family Members of Adults with PTSD on Quality of Life

Study; Follow-Up | N | Intervention and Comparator | Quality of Life Outcomes
Internet interventions
Crenshaw 2023^74^; 1 month | 27 | Couple HOPES (pre-post) | Significant improvement in QOL on the WHOQOL from baseline to PT (g [95% CI] = 0.56 [0.10, 1.02]), but not from baseline to 1-month follow-up (g [95% CI] = 0.61 [−0.04, 1.26]).
Erbes 2020^72^; PT | 46 | VA-CRAFT compared to waitlist | No significant difference between groups at PT on the WHOQOL-BREF for psychological QOL (F[1, 12] = 2.00, eta^2^ = 0.05) or relationship QOL (F[1, 12] = 1.18, eta^2^ = 0.03).
Morland 2023^76^; PT | 15 | Couple HOPES (pre-post) | No change in BBQ scores from baseline to PT (g = −0.05, p = .326).

Abbreviations. BBQ= Brunnsviken Brief Quality of Life Scale; CI=confidence interval; iCBT=internet-based cognitive behavioral therapy; PT=posttreatment; QOL=quality of life; WHOQOL=World Health Organization Quality of Life; WHOQOL-BREF= World Health Organization Quality of Life – Brief.