# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023471333 (https://www.crd.york.ac.uk/prospero/display_record.php?RecordID=471333)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions (KQs) were the focus of this review:

Key Question 1 | Are internet and mobile interventions with asynchronous therapist-guided or self-guided content and resources designed to improve PTSD symptom severity and/or self-management effective for improving PTSD symptoms and other mental health symptoms among adults with a diagnosis of PTSD?
Key Question 2 | Are internet and mobile interventions with asynchronous therapist-guided or self-guided content and resources designed to enhance coping and symptom management skills for family members and caregivers of adults with PTSD effective for improving stress, mental health symptoms, and coping skills?

### Eligibility Criteria

Study eligibility criteria are shown in the table below. We included studies where a substantial portion of the sample (about half, at minimum) met criteria for probable PTSD, as defined by the study. For studies meeting these criteria, we used a best-evidence approach and prioritized evidence from randomized controlled trials (RCTs) and cohort studies, when available.

Population | KQ1: Adults diagnosed with PTSD using a validated clinician-administered or self-report PTSD instrument.; KQ2: Family members and caregivers of adults diagnosed with PTSD.
Intervention | KQ1: Internet and mobile interventions with asynchronous therapist-guided or self-guided content and resources designed to improve PTSD symptom severity and/or self-management. Interventions may address mental health or medical comorbidities, provided the intervention includes components to address PTSD symptoms.; KQ2: Internet and mobile interventions with asynchronous therapist-guided or self-guided content and resources designed to enhance coping and symptom management skills of family members and caregivers of adults with PTSD.; For both KQs, therapist guidance associated with the internet or mobile intervention cannot exceed 5 hours. There are no restrictions on the number of interactions with a therapist or the length of the program, and interventions may be delivered alone or in conjunction with other psychological interventions.
Comparator | Alternate intervention, treatment as usual, waitlist control, post-intervention (pre-post studies).
Outcomes | KQ1: Mental health symptom severity, functioning/quality of life.; KQ2: Stress or mental health symptom severity, coping skills.
Setting | We will include studies conducted in the US or comparable countries (OECD member countries).
Study Design | Any comparative or pre-post studies will be eligible, but we may prioritize more rigorous designs in our synthesis.

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, PsycINFO, PTSDPubs, and the Cochrane Central Register of Controlled Trials through October 2023 using terms for PTSD and internet and mobile interventions (see Appendix for complete search strategies). Additional citations were identified from clinicaltrials.gov and hand-searching reference lists of relevant systematic reviews. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. When needed effect information was reported only in plots or other graphics, we abstracted data using the WebPlotDigitizer tool (https://apps.automeris.io/wpd/). Data abstraction was first completed by 1 investigator and checked by another. The internal validity (risk of bias) of each included study was rated using the Cochrane Risk of Bias 2.0 tool for randomized controlled trials^30^ and the ROBINS-I tool for non-randomized studies.^31^ Internal validity ratings were completed independently by 2 investigators. Disagreements were resolved by consensus or discussion with a third reviewer (see Appendix for risk of bias ratings).

## SYNTHESIS

Available evidence was synthesized using a best-evidence approach,^32^ prioritizing findings from RCTs and cohort studies over pre-post studies. Findings were organized by key question, outcome, and outcome assessment timing (immediately post-treatment, 1-3 month follow-up, or longer-term follow-up). For KQ1, PTSD and depression symptom severity were primary outcomes, and we did not conduct strength of evidence assessment on other outcomes. Although not originally planned, a sufficiently large number of studies were identified in Veterans or active-duty service members to allow reporting of primary outcomes separately for military and civilian populations.

We were also interested in intervention and study methodological characteristics that may influence intervention effects on PTSD and depression symptoms severity. These characteristics were 1) intervention modality (internet, app, or SMS/text message), 2) level of facilitation, 3) intervention duration, 4) presence or absence of a written exposure component (CBT-based interventions only), 5) outcome assessment method (clinician-administered or self-reported measure), and 6) comparison group type (active control, in-person therapy, minimal contact, intervention without exposure component, intervention without guidance, psychoeducation only, treatment as usual, or waitlist control). Level of facilitation was categorized as none (reminders or technical support only), minimal support (guidance/feedback on writing assignment or homework and/or other minimal unstructured support), or direct facilitation (provider directly delivers some aspect of intervention). Intervention duration was categorized as brief (1 week or less or a single session), moderate (2-5 weeks), long (6 weeks or longer), or self-guided timeline. Virtually all interventions used CBT or were informed by CBT principles, so it was not feasible to compare effects of CBT and non-CBT interventions.

Between-group differences in PTSD and depression symptom severity at each assessment point were represented as bias-adjusted standardized mean differences (SMDs; Hedges’ g). Several included studies also reported the proportion of patients with clinically significant PTSD symptom improvement; the proportion who recovered, were in remission, or no longer met PTSD diagnostic criteria; and/or the proportion with reliable PTSD symptom improvement or change. Odds ratios (ORs) were used to quantify between-group differences in these outcomes.

Effect estimates for primary outcomes were synthesized with hierarchical random-effects models, given that many studies reported multiple measures of the same construct and/or assessed the same outcome at multiple time points (even after subgrouping effect estimates into the assessment timeframes described above). Models assumed a correlation of 0.7 between measures of the same outcome construct and 0.9 between assessment time points (ie, autocorrelation). Cluster-robust confidence intervals and degrees of freedom calculated using the Satterwaithe approximation were used for models of dependent effect estimates. Conventional random-effects models were used when included studies each contributed a single effect estimate. Regardless of modeling approach, analyses with fewer than 10 studies incorporated the Knapp-Hartung method or comparable adjustment to standard errors. Meta-regression models used to investigate moderation by intervention and study characteristics included all effect estimates regardless of assessment time point, accounting for dependencies among estimates in the same fashion as main analyses. Meta-analyses were conducted using the metafor^33^ package for R (R Foundation for Statistical Computing, Vienna, Austria).

Between-study variation in effects (heterogeneity) was estimated using restricted maximum-likelihood estimation, and in moderation analyses, the amount of heterogeneity was allowed to differ across study subgroups. For all analyses, heterogeneity is presented as 95% prediction intervals (PIs). Prediction intervals describe the likeliest range of true effects (eg, true differences in PTSD symptoms between groups) across studies and provide an estimate of the magnitude and direction of effects that would be found in future studies similar to those included in a synthesis.^34^ A PI encompassing effects similar to the overall estimate suggests limited heterogeneity, whereas a PI that includes effects in the same direction as the overall estimate but that vary widely in magnitude (ie, small to large benefits) suggests moderate heterogeneity. If a PI encompasses effects that range widely in both magnitude and direction, then substantial heterogeneity is likely present. Prediction intervals were evaluated alongside forest plots to reach conclusions about whether effect estimates in a given analysis were consistent, moderately inconsistent, or highly inconsistent.

### Strength of Evidence

After synthesizing available evidence, we rated the strength of evidence based on the methodology and risk of bias of available studies, the consistency and certainty of findings, and the directness of outcomes (whether reported outcomes are relevant to patients and providers).^35^ For this review, we applied the following general algorithm: high strength evidence consisted of multiple trials with low risk of bias, consistent and precise findings, and clinically relevant outcomes; moderate strength evidence consisted of multiple trials with low to unclear risk of bias, consistent and precise findings, and clinically relevant outcomes; low strength evidence consisted of a single trial, or multiple small trials, with unclear to high risk of bias, inconsistent or imprecise findings, and/or outcomes with limited clinical relevance; and insufficient evidence consisted of a single trial with unclear or high risk of bias.