# BACKGROUND

Approximately 10% of United States (US) military Veterans experience posttraumatic stress disorder (PTSD) at some point in their lifetime,^1^ with nearly one-quarter of Veterans reporting significant posttraumatic stress (PTS) symptoms.^2^ Untreated PTSD is associated with significant functional impairment,^3^ high rates of psychiatric^4^ and medical comorbidities,^5^ substance misuse,^6^ and death by suicide.^7^ Veterans with PTSD engage in high levels of healthcare utilization^8^ and pursue disability compensation at a high rate.^9^ Individual face-to-face trauma focused treatments, to include trauma-focused cognitive behavioral therapies (CBT) and eye movement desensitization and reprocessing (EMDR), have been identified as the most effective treatments for PTSD and are considered first-line treatments.^10^ The Department of Veterans Affairs (VA) and Department of Defense (DoD) have invested significant resources in developing and broadly implementing clinical pathways that incorporate effective therapeutic approaches.^11^ Routine screening and access to evidence-based treatment for PTSD are now standard practices across all VA medical facilities.^12^ However, despite these considerable investments in care, the majority of the military population (Veterans and military service members) with PTSD do not access and benefit from PTSD treatments.^13,14^

Increasing access to effective PTSD treatments is a high priority for the VA and DoD. Veterans endorse several obstacles that may prevent them from engaging in PTSD treatment such as shame and stigma, fear of social consequences, and logistical challenges.^15–17^ Virtual treatments for PTSD that offer more flexible treatment delivery options with reduced provider requirements have the potential to overcome many of these barriers, especially given Veterans’ receptivity to home-based telehealth options.^17,18^ Over the past 2 decades several types of technology-assisted treatments for PTSD have been developed and tested.^19^ Internet and mobile interventions have also been developed to support family members and caregivers of adults with PTSD who often experience psychological distress and caregiver burden related to their relationship.^20^ These interventions aim to overcome similar access barriers to improve family member/caregiver wellbeing.

Virtual treatments, in which a provider delivers evidence-based therapies via synchronous telehealth, are now largely considered equivalent to in-person therapy for PTSD.^21,22^ Self-guided, asynchronous PTSD treatments that use the internet or mobile phone applications (apps) have also become available in recent years. These interventions, which differ in level of therapeutic support but are generally lower intensity than conventional in-person therapy, have the potential to expand access to effective PTSD therapies to anyone with the internet or a smartphone.

Internet treatments are generally structured interventions that deliver therapeutic content over the internet with varying levels of provider guidance.^23^ Recent reviews indicate that internet-based cognitive behavioral therapies (iCBTs) may be more effective in reducing PTSD symptoms relative to waitlist conditions.^24^ Although iCBTs are generally rated favorably by participants, high dropout rates present a limitation to these treatments.^25^ Mobile mental health apps use smartphone technology to offer self-directed or remotely facilitated therapeutic content.^26^ The evidence supporting these newer treatment approaches is mixed. Two recent reviews evaluating apps for the treatment of PTSD detected no significant benefits of these interventions relative to a control comparison,^27,28^ while a more recent review detected a small effect of stand-alone, smartphone-based mental health apps.^29^

There is considerable variation among existing internet and mobile interventions in terms of treatment modality used (ie, delivered over the internet, an app, or SMS), the content and duration of the treatment, the extent and nature of facilitation, and the targeted population of the treatment. Studies also differ in whether they compare interventions to no treatment (waitlist or treatment as usual), active control conditions, or in-person therapy. Examining how these factors impact treatment effectiveness can help inform implementation considerations. Given the potential benefits and broad accessibility of internet and mobile interventions for PTSD, the aim of this review is to synthesize available evidence on the effectiveness of internet and mobile interventions (with asynchronous therapist-guided or self-guided content and resources) for adults with PTSD and their family members or caregivers.