# PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
3 | 3 | No - This report focused mainly on CBT as the internet and mobile app intervention for the treatment of PTSD. There are many other apps that are developed by the VA for the treatment of PTSD and PTSD Co-occurring conditions such as pain, depression, and suicide. Some of these apps are used as adjunctive therapies and others are used in place of CBT. Examples included, ACT, CBT-CP, Mindfulness, etc. It would be apropos to broaden the scope to include the additional apps. | Thank you for expressing your concern about the scope of the review. Studies of internet interventions and apps that aim to manage symptoms of PTSD, with or without components aimed to manage other, comorbid conditions, would have been included in this review if they had met the eligibility criteria for the review, regardless of whether the intervention was CBT-based. Often, studies were excluded because participants (at least 50%) did not meet criteria for a diagnosis of PTSD or probable PTSD or the study did not have a control group.
4 | 4 | Yes | None
5 | 5 | Yes | None
6 | 6 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | No | None
8 | 2 | No | None
9 | 3 | No | None
10 | 4 | No | None
11 | 5 | No | None
12 | 6 | No | None
Are there any published or unpublished studies that we may have overlooked?
13 | 1 | No | None
14 | 2 | No | None
15 | 3 | No | None
16 | 4 | No | None
17 | 5 | No | None
18 | 6 | No | None
Additional suggestions or comments can be provided below.
19 | 1 | Outstanding summary - thanks very much. | Thank you
20 | 2 | For the first bullet under “future research,” I think it would be helpful to add 1-2 examples of the types of populations that might be more/less receptive to digital treatments. I think when people think of the word “population,” demographic groups come to mind, but I don’t think that is what is meant here as that is covered by the next bullet. Judging by the evidence reviewed, it seems like these populations could be treatment-naive patients, or those with subclinical distress. | Based on the updated results, we have now modified some of the future research conditions. As iCBTs demonstrated limited effectiveness across the military samples, we now suggest that future treatments may want to consider targeting treatment-naïve patients in line with a promising civilian trial (Bisson et al, 2022).
21 | 2 | This bullet in future directions seems worthy of splitting up into two. They are both important ideas that should be elaborated upon a little more: “Evaluating strategies to increase treatment adherence to online protocols and the optimal amount of guidance needed for treatments” | We have now modified our Future Directions section in line with our updated results.
22 | 2 | I also think the report’s overall conclusions and recommendations for future directions should be elaborated upon further in the executive summary, both in the initial bullets and in the narrative. I realize these are supposed to be brief summaries, but this may be all that some people read, and I think these are crucial points from the report. At present, there is one bullet that contains a lot of high-level information, and there is one concluding sentence in the narrative. I would like to see a little more. | We have elaborated on the executive summary to include a more robust summary of the conclusions and recommendations.
23 | 3 | It is not clear why this report included studies done in other countries with non-Veterans participants. | The eligibility criteria decided on for this report, in collaboration with the Operational Partners, was not limited to US Veterans. However, we highlight studies conducted among US Veterans throughout the report as the evidence with the greatest relevance/applicability and now report results separately for this population, when possible.
24 | 4 | Page vi, line 53: Says 2 studies found no difference between internet and in person. Were they non-inferior studies? | Thank you for your question. The executive summary was edited and no longer mentions these 2 studies. However, we discuss these 2 studies in the results section; 1 was a non-inferiority study and the other was not (the second was a small feasibility study).
25 | 4 | Page vii, line 43: Table subheading: PTSD appears twice. Why? | Headings are set to repeat at the start of a new page.
26 | 4 | Page 4, line 18: I would state in PICOTS that over half of sample had to probable PTSD. | We include a statement above the eligibility criteria explaining that we required “about half, at minimum” of the study sample to have probable PTSD. We did not use a hard cut-off of 50% (we included 1 study with 48.4% of the sample having probable PTSD).
27 | 4 | Page 5, line 21: Studies could have clinician administered or self report outcomes. could results be reported separately? | We have added a subgroup analysis examining whether intervention effects differed based on use of a clinician-administered or self-reported outcome measure.
28 | 4 | Page 10, line 15: Is it 34 or 36 RCTs? On line 7 it is 36 and on line 15 it is 34. | There were 36 RCTs included total, but the literature overview is then divided into 2 sections characterizing the PTSD studies and the family member/caregiver studies separately. 34 of the RCTs were on interventions for individuals with PTSD and 2 RCTs were on interventions for family members or caregivers of individuals with PTSD.
29 | 4 | Page 13, line 19: I would include % with PTSD in the table under population. | Thank you for your suggestion. We have added % PTSD to the study characteristics table.
30 | 4 | Page 19, line 11: Could there be subgroup analyses on PTSD v subthreshold? Veteran/active duty v community? | Thank you for your suggestions. We did not conduct subgroup analysis examining PTSD vs subthreshold PTSD due to the high degree of variation between studies in how PTSD/probable PTSD was measured and defined. We have conducted additional subgroup analysis examining Veteran/active-duty vs community samples and have added this to the results.
31 | 4 | Page 51, line 19: Bias in measurement of outcome. How was self-report rated? The way I think about it, if the assessor was not blinded, then the domain rating will be some concerns or high. It will be some concerns if either 4.4 or 4.5 are answered No (4.4: Could assessment of the outcome have been influenced by knowledge of intervention received?; 4.5: Is it likely that assessment of the outcome was influenced by knowledge of intervention received?). The measures are not objective (like a blood test), so 4.4 is always Yes. The answer for 4.5 depends on the comparator condition, we have instructions that if the comparator (any arm) is inactive control then we’d rate that as Yes (there are some other circumstances where that would be rate Yes but they are less common). If 4.5 is rated yes, then the domain rating would be High (and that means the overall rating would also be High). | Thank you for your comment. We did not consider self-reported outcomes as a major concern for bias compared with clinician-reported outcomes, given that both assessment methods rely on patients’ reporting of symptoms (consistent with many mental health treatment contexts). We did consider outcome assessment method to be a potential source of variability in effects across studies, however, and we have included more detailed reporting of results by assessment method. Regarding blinding, studies that did not blind patients to intervention assignment and used an active comparison condition were judged to have some concerns in this domain, while studies that did not blind patients to intervention assignment and used an inactive comparison condition were considered high risk of bias in this domain (and consequently, overall). Finally, because eligibility was limited to studies of individuals with an existing PTSD diagnosis, we did not consider use of self-reported outcome measures to be tantamount to unblinded intervention assignment. We have changed some of the ratings to be consistent with this approach.
32 | 4 | Page 55, line 52: Why is unblinded CAPS rated higher than self-report? | Studies with self-reported PTSD outcomes were only rated lower than studies with clinician-administered PTSD outcomes administered by unblinded assessors in cases where the participants were blind to group assignment or they were not blind to group assignment, but the study used an active comparison condition.
33 | 4 | Page 61, line 55: Seems like bias for measurement should be assessed separately for each outcome. There was a blinded CAPS and self-report. CAPS should be low concern. | As mentioned above, we did not consider self-reported outcomes as a major concern for bias compared with clinician-reported outcomes, given that both assessment methods rely on patients’ reporting of symptoms (consistent with many mental health treatment contexts). We did consider outcome assessment method to be a potential source of variability in effects across studies, however, and we have included more detailed reporting of results by assessment method.
34 | 4 | Page 64, line 24: Same as above. There is a blinded CAPS, therefore doesn’t seem like high RoB | Given that the CAPS relies on patients’ reporting of symptoms, we were concerned with blinding of the participants as well as blinding of the outcome assessors.
35 | 5 | This is a phenomenally well-synthesized review of the extant lit on technology-based interventions for PTSD and their sequelae. Authors lay out the existing value and future potential of internet and tech-based interventions, results appear to be accurately reported, and conclusions drawn by authors are both appropriate and clinically valuable. | Thank you for this comment.
36 | 5 | I am somewhat surprised that the title of this evidence synthesis effort refers to “clinical and at-home resources.” This title is confusing and somewhat misleading, since the review seems to focus exclusively on tech-based resources. I might suggest a title revision, if possible, to reflect the subject of the review. | Thank you for this comment. We have changed the title to reflect the aims of the review more closely.
37 | 6 | The “Clinical and At-Home” part of the title is somewhat misleading. | Thank you for this comment. We have changed the title to reflect the aims of the review more closely.
38 | 6 | On page 11, it would help to clarify who was required to have the PTSD diagnosis in the 3 studies mentioned (the patient or the family member?). | We have edited this sentence to make it clearer that we are referring to the PTSD patient.
39 | 6 | My biggest question is which studies were testing trauma-focused CBT vs. more general CBT skills? Similar to the way the authors examined the inclusion of imaginal exposure as a subgroup, this could be examined. | This is a great question and prompted us to take a deeper dive into the specific treatments tested. Given the differential treatment effects for military vs civilians, and the few military studies that evaluated a TF-CBT (4) we decided not to statistically analyze this. However, we did include more details about the included military studies on whether they were CBT vs. TF-CBT, and what TF-CBT frameworks they are based on. We dedicate a paragraph to this topic in our Discussion and reference it as part of our Future Directions.