# RISK OF BIAS ASSESSMENTS

## RANDOMIZED CONTROLLED TRIALS (ROB-2)

Trial Name or Author Year | Bias from randomization process | Bias from deviation from intended interventions (Assignment) | Bias from deviation from intended interventions (Adherence) | Bias from missing outcome data | Bias in measurement of outcome | Bias in selection of reported result | Overall risk of bias (Low, Some concerns, High)
Acosta 2017 | Some concerns; Permuted block randomization based on diagnoses. Allocation concealment not described. No significant baseline differences between groups. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | High; 38.3% of treatment group completed all modules. Greater # lost to follow-up in treatment group than TAU only group. Analysis included all randomized participants. Both groups had access to usual VA primary care services and groups did not differ in amount of care received. Psychotropic medication use not reported. | Some concerns; All randomized participants included in analysis (ITT), but methods of handling missing data not described. | High; Combination of clinician-administered and self-report measures that rely on participant report of symptoms. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Primary outcomes specified in protocol were reported. | High
Allen 2022 | Low; 1:1 random allocation conducted by an independent individual. No significant baseline differences between groups. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 66.7% of treatment group completed all modules. Similar # withdrawals between groups. Both groups could not be currently receiving PTSD treatment and had to have stable medication regimen. Psychotropic medication use not reported. | Some concerns; ITT analysis does not include participants who withdrew or didn’t complete baseline assessment (4 in treatment group, 5 in waitlist). Missing data handled with model-based imputation (maximum likelihood estimation). | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; 6-month outcomes not reported; some secondary outcomes of interest not reported (Sheehan Disability Scale, WHODAS-II) | High
Andersson 2021 | Low; Computer-generated randomization conducted by an independent individual. No baseline differences reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | High; 18.8% of treatment group completed all modules. 15.6% dropout in treatment group and 3.1% in control group. Both groups could not be currently receiving psychological treatment. Psychotropic medication use not reported. | Low; All randomized participants included in ITT analyses. Missing data handled with model-based imputation. | High; Combination of clinician-administered and self-report measures that rely on participant report of symptoms. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified | High
Berdard-Gilligan 2022 | High; Randomization was likely appropriate and concealed, but baseline symptoms on the primary outcomes significantly differed in Wave 1 suggesting different levels of sx severity between groups. | Low; Intervention groups were similar (only the content of the texts differed) and it is unclear whether participants were notified or aware of group assignment. No reported deviations from intended intervention. | Some concerns; Co-interventions was just included as a binary outcome and there was not exclusion criteria about current treatments. | Unclear; A small number of participants were not included in analysis. Investigators did not provide details about these participants or why they were not analyzed. | Some concerns; Outcomes were self-report measures. Unclear whether participants were blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; The study was not pre-registered. | High
Bedford 2023 | Low; Computer-generated randomization within the online survey system. No baseline differences reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Low; Single session intervention; appears all participants completed the session. No information provided on receipt of concurrent therapy. 53.3 % reported taking psychotropic medications, but % for each group not provided. | Low; 23.7% int. vs 27.3% control without follow-up assessment. All randomized participants included in ITT analyses. Missing data handled with multiple imputation. | Some concerns; Outcomes were self-report measures. Participants were not blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | Some concerns
Bisson 2022 | Low; Computer-generated allocation sequence conducted by a data manager who emailed allocation to the trial manager. Control group had higher level of education. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 79.4% of participants in the iCBT-TF group and 55.6% in the face-to-face CBT-TF group met the a priori definition of full adherence, but definitions of adherence were different for each group. Both groups could not be currently receiving psychological treatment and had to have stable medication regimen. Psychotropic medication use not reported. | Low; 71-74% completed follow-up. All randomized participants included in ITT analyses. Missing data handled with multiple imputation. | Some concerns; Combination of clinician-administered and self-report measures that rely on participant report of symptoms. Participants were not blind to group assignment, but an active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | Some concerns
Clausen 2019 | High; First 13 participants were randomly assigned by the lab manager (unclear method). Other research staff were blind to allocation sequence. Last 7 participants were assigned to treatment group (not randomly). Baseline differences not reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 57% in intervention group and 50% in placebo group received full training. Required stable dose of antidepressant or sleep medications (2 PTSD participants reported stable dose of antidepressants). No information on concurrent therapy. | High; Completer analysis (analyses did not include withdrawals; 42% int. and 50% control). | Some concerns; Outcomes were self-report measures. Participants were not blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | High
De Kleine 2019 | Some concerns; Computer-generation randomization within the online platform. The active group was significantly older than the control group and reported less exposure to trauma during childhood and less violence/physical assault in adulthood. | Low; Participants blinded to group allocation. No reported deviations from intended intervention. | Low; 97% completed all treatment sessions. The number of participants receiving trauma-focused therapy or psychotropic medications did not differ between groups. | Some concerns; 61% active vs. 72% control had data at 6 months. All randomized participants were included in analyses, but unclear handling of missing data in ITT analysis. | Some concerns; Outcomes were self-report measures. Participants appear to have been blind to group assignment and an active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; Unable to access trial registration | Some concerns
Engel 2015 | Low; Centrally conducted random permuted blocking scheme. Does not state how sequence was generated. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 35% of the treatment group completed all logins. Excluded individuals actively engaged in trauma-focused treatment or with an unstable medication regimen. Psychotropic medication use not reported. | Low; 82.% had complete data. No difference in missing data between groups. All randomized participants included in ITT analyses. Missing data handled with model-based imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
Erbes 2020 | Some concerns; Details of sequence generation/allocation concealment not reported. Baseline differences not reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 56% of participants in the treatment group completed the entire course. Initiation of mental health care was an aim of the study/outcome of interest: 36% treatment group vs. 21% control. Psychotropic medication use not reported. | Some concerns; Completer analysis; 5 (11%) randomized participants not included in analyses (2 treatment group participants that did not initiate the treatment, 3 participants missing data at posttreatment). | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | High
Fonzo 2019 | Low; Computer-generated random sequence; allocation was concealed prior to randomization of each participant. No significant baseline differences. | Low; Participants blinded to group allocation. No reported deviations from intended intervention. | Some concerns; Rates of adherence to completing the minimal adequate dose were 77% in the active arm and 75% in the control arm. Participants could not be currently engaged in psychotherapy and, if on antidepressant medications, had to be on a stable regimen. Psychotropic medication use not reported. | Some concerns; 35% of total sample dropped out. All randomized participants included in analysis; missing data handled with model-based imputation. | High; Combination of clinician-administered and self-report measures that rely on participant report of symptoms. Participants were blind to group assignment and an active comparison condition was used, but assessors administering the CAPS were not blind to group assignment. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | High
Gawlytta 2022 | Low; Computer-generated random sequence; performed centrally by an independent individual. Duration of mechanical ventilation among ventilated patients greater in treatment group. | Low; Participants blinded to group allocation. No reported deviations from intended intervention. | Some concerns; Treatment adherence unclear. Excluded patients with ongoing therapeutic treatment. Psychotropic medication use not reported. | Low; Up to 15% missing data. All randomized participants included in ITT analyses. Missing data handled with multiple imputation. | Some concerns; Outcomes were self-report measures. Participants were blind to group assignment. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | Some concerns
Hensler 2022; Hensler 2023 | Low; Computer-generated allocation sequence; sequence generated by an external statistician; allocation concealed from research team. Baseline differences not reported. | Some concerns; Blinding of participants not feasible. At follow-up, 4 participants on the waitlist reported having used PTSD Coach. | Some concerns; 19% participants with access to the app stated that they had not used PTSD Coach. 7 participants (app access=4; waitlist=3) reported using a self-management app other than PTSD Coach. Participants started psychological treatment (app access=10; waitlist=10), changed their medication (app access=8; waitlist=10), or started a new medication (app access=10; waitlist=8). 26 people sought professional help related to their trauma (app access=17; waitlist=9). | Low; 77-85% had complete data. All randomized participants included in ITT analyses. Missing data handled with multiple imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | High
Hirai 2020 | Some concerns; Only states that participants were randomly assigned. No significant baseline differences. | Some concerns; Unclear whether participants were blind to group assignment (interventions were similar). No reported deviations from intended intervention. | Some concerns; 34% of participants never started the first writing session. 48% completed intervention and follow-up assessments (only completers were analyzed). Co-interventions not reported. | High; Completer analysis; only includes 48% of participants randomized. | Some concerns; Outcomes were self-report measures. Unclear whether participants were blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
Ivarsson 2014 | Low; Computer-generated randomization sequence; randomization conducted by an independent individual. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 68% completed a minimum dose as defined by investigators. 22.6% of intervention group and 29% of waitlist were taking psychotropic medication at baseline. Excluded participants with ongoing psychological treatment. | Low; Response rate 87%. All randomized participants included in analysis; missing data handled with model-based imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
Knaevelsrud 2007 | Some concerns; Computer-generation randomization; allocation concealment not described. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 16% did not complete treatment (dropped out), but no information provided on adherence. Participants could not be receiving treatment elsewhere. Psychotropic medication use not reported. | Low; 84% completed follow-up. Analyses included all randomized participants, but missing data was handled with simple imputation of baseline scores. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; Unable to access trial registration. | High
Krupnick 2017 | High; No detail provided on sequence generation or allocation concealment methods. Intervention group had significantly lower baseline intrusion and hyperarousal symptoms, and lower PCL total scores than those in the TAU group. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | High; No information provided on adherence to intervention. 4 TAU pts began and 1 completed a course of CPT during the course of the study. The average number of psychosocial treatment sessions was 2.44 for TAU and 0.78 for intervention group. Antidepressant medication use was similar between groups. | High; 25% in treatment group and 67% of TAU who completed the baseline assessment completed the follow-up assessment. ITT analyses included participants who completed the baseline assessment (did not include 3 randomized participants). Missing data was handled with model-based imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
Kuhn 2017 | Low; Computer-generated randomization sequence; randomization conducted by the study coordinator. Significant baseline differences in psychosocial functioning scores only. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; Intervention was access to the app; do not report how many participants in the intervention group used the app. Participants could not currently be in PTSD treatment. Psychotropic medication use not reported. | Low; 82% int. and 90% control responded at 3 months. All randomized participants included in ITT analyses. Missing data handled with multiple imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used with exception of PTSD coping self-efficacy. | Some concerns; No protocol identified. | High
Lange 2003 | Low; Computer-generated randomization sequence. Allocation concealment not described. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 36% in intervention group did not complete treatment; no additional information provided on adherence. Participants could not currently be in treatment elsewhere. Psychotropic medication use not reported. | High; Only treatment completers were asked to complete follow-up assessment; 28% of randomized participants did not have follow-up data. Repeated main analysis with ITT sample (all participants randomized); missing data was handled with simple imputation of baseline values. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | High
Larsen 2019 | Some concerns; Only states that participants were randomly assigned. No significant baseline differences. | Some concerns; Appears that participants were blind to group assignment (interventions were similar). No reported deviations from intended intervention. | Some concerns; 72% of randomized participants overall were treatment completers (completed at least 80% of training sessions). There was no difference between groups on average number of completed training sessions. All but 3 participants (all in intervention group) were receiving other treatments. 3 participants in each group had a notable change in treatment status during the study. | High; Only treatment completers were asked to complete follow-up assessment; 28% of randomized participants did not have follow-up data. Repeated main analysis with ITT sample (all participants randomized); missing data was handled with simple imputation of baseline values. | Some concerns; Outcomes were self-report measures. Participants appear to have been blind to group assignment and an active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported. | High
Lehavot 2021 | Low; Design paper specifies computer-generated randomization sequence. Baseline differences not reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; The intervention group had a lower proportion of treatment completers than the phone monitoring group (76% vs 96%); completion defined as >50% sessions. Participants could not be currently in treatment; had to have stable dose of medications. Psychotropic medication use not reported. | Low; Over 80% randomized completed all follow-up assessments. Analyses included all randomized participants (ITT); missing data handled with model-based imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; Secondary outcomes specified were not reported (depression, quality of life) | High
Lewis 2017 | Low; Randomization sequence generated by an independent statistician. Allocation was concealed with sealed, opaque envelopes. Baseline differences not reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 36% in treatment group completed all 8 modules, 72% completed more than half. Participants could not be currently in treatment; had to have stable dose of medications. Psychotropic medication use not reported. | Low; 71% in treatment group and 81% in waitlist completed post-treatment assessment. Analysis includes all randomized participants (ITT); missing data handled with multiple imputation. | High; Combination of clinician-administered and self-report measures that rely on participant report of symptoms. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
Littleton 2016 | Some concerns; Randomization sequence generated with a computerized coin flip. No information provided on allocation concealment. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | High; 16% randomized did not complete baseline assessments and log in to program at least once. 16% in treatment group completed the entire program. Participants could not be currently in treatment; had to have stable dose of medications. Psychotropic medication use not reported. | Some concerns; 43% of treatment group and 29% of control group did not have follow-up data. ITT analyses was conducted; missing data were handled with multiple imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
Litz 2007 | Some concerns; Details of sequence generation and allocation concealment not described. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 73% completed treatment; no additional information on adherence provided. Participants could not be currently in treatment; had to have stable dose of medications. Psychotropic medication use not reported. | Some concerns; 31% of participants overall did not complete post-treatment assessment. ITT analysis conducted, but ITT group is not defined; missing data handled with model-based imputation. | Some concerns; Combination of clinician-administered and self-report measures that rely on participant report of symptoms. Participants were not blind to group assignment, but an active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | Some Concerns
McGuire 2023 | Low; Computer-generated randomization sequence. Study staff remained blind to sequence until assignments were made. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 63% completed all 8 sessions in the treatment condition. Veterans were not excluded if they were currently enrolled in other treatments; no information on outside treatment reported. | High; Completer analysis; 67% in intervention group and 83% in control group were included in analyses. Handling of missing data not described. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
McLean 2021 | Some concerns; Block randomization; methods of sequence generation and allocation concealment not described. Baseline differences not reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; 42% in web-PE and 81% in face-to-face control group completed all 10 sessions, but the number of sessions completed was not significantly different between groups. Excluded participants currently engaged in evidence-based treatment for PTSD. Psychotropic medication use not reported. | High; 53% lost to follow-up in web-PE group at post-treatment, 48% of face-to-face control. Unclear whether analyses include all randomized participants, Ns not provided; handling of missing data not described. Design paper states that all participants who provide any outcome data will be included. | Some concerns; Combination of clinician-administered and self-report measures that rely on participant report of symptoms. Participants were not blind to group assignment, but an active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Not all secondary outcomes specified in design paper reported, but primary outcomes are reported. | High
McLean 2022 | Some concerns; Computer-generated randomization sequence. Randomization conducted by study RA; allocation concealment unclear. Baseline differences not reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; There was a bug that caused one app feature to crash and was corrected halfway through the study. All received the intervention except 1 in app alone group. Unclear adherence to intervention. Co-interventions not reported. | Low; 23% app alone, 6% app + support, 19% waitlist lost to follow-up at posttreatment. All randomized participants included in analyses (ITT); missing data handled with model-based imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Not all secondary outcomes specified in design paper reported, but primary outcomes are reported. | High
Miner 2016 | Some concerns; Methods of sequence generation and allocation concealment not described. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; No participants in treatment group reported never using the app; further adherence information not provided (intervention was access to the app only). Participants could not currently be in PTSD treatment. Psychotropic medication use not reported. | Low; 8% in app group and 13% in waitlist did not complete posttreatment assessment. All randomized participants included in ITT analyses. Missing data handled with multiple imputation. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
Morabito 2023 | Some concerns; Randomization sequence generated with random number table; allocation concealment not described. Greater # of Hispanic participants in control group; higher baseline negative affect in treatment group. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Low; 1 participant in the treatment group and 2 in the control group did not complete the intervention (defined as spending more than 2.5 SDs less than mean time). Stable medication regimen required; no information on other ongoing treatment. | Some concerns; Excluded 3 participants who did not complete the intervention and 2 with impairing drug use during the intervention (10% of randomized participants). Missing data handled with model-based imputation. | Some concerns; Outcomes were self-report measures. Participants were not blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; PANAS, TIQ, LEC, PTCI not mentioned in trial registry. Guilt mentioned in registry but not paper. | Some concerns
Nieminen 2016 | Low; Computer-generated randomization sequence; randomization conducted by independent individual. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; In treatment group, 54% completed all 8 weeks of treatment and 67% completed at least four modules. Excluded individuals currently participating in psychotherapy. Required stable medication regimen. Psychotropic medication use not reported. | Some concerns; 64% int. vs 96% control completed interview. 86% int. vs 96% control completed questionnaire. Flow diagram shows drop-outs excluded from analysis, but table shows ITT with missing data imputed. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. One of the self-report PTSD scales is preliminarily validated. | Some concerns; No protocol identified. | High
Possemato 2011 | Some concerns; Methods of sequence generation and allocation concealment not described. Intervention group participants were significantly more likely to be separated or divorced than control participants. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; All intervention group participants completed all 3 writing sessions. 1 in intervention group and 4 in control group sought outside treatment. | Some concerns; Excluded 5 participants who received other treatment during the study period from ITT analyses. Unclear handling of missing data. | Some concerns; Outcomes were self-report measures. Participants were not blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | Some concerns
Possemato 2016 | Some concerns; Methods of sequence generation and allocation concealment not described. Baseline differences present in social QOL scores. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; All participants completed every treatment session & fidelity to treatment was high among clinicians delivering the treatment. Participants in the clinician-supported group had more days of app use compared to the self-managed group, but full usage data was not available. Participants could not be currently in mental health treatment; had to have stable dose of medications. Psychotropic medication use not reported. | Low; Missing data handled with multiple imputation. All participants in the clinician-supported group and 80% in the self-managed group completed the posttreatment assessment. ITT analysis included all randomized participants. | Some concerns; Outcomes were self-report measures. Participants were not blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; Unclear whether outcome assessors were blind to group assignment. Outcomes were self-report measures and participants were not blind to group assignment. Validated outcome measures used. | Some concerns
Possemato 2019 | Some concerns; Permuted block randomization; no information on methods of sequence generation or allocation concealment. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Some concerns; Participants in both conditions completed an average of 11 modules, but more participants completed at least 1 module in the peer support group than the self-managed group (93% vs 73%). Fidelity of peer support specialists appears to have been moderate. Participants could not be currently in mental health treatment; had to have stable dose of medications. Psychotropic medication use not reported. | High; Only included participants who competed follow-up assessment in analysis; did not include 33% of randomized participants. Missing data from included participants was handled with model-based imputation. | Some concerns; Outcomes were self-report measures. Participants were not blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Validated outcome measures used. | Low; Outcomes specified in protocol were reported (except that a different version of the PCL was used). | High
Spence 2011 | Low; Computer-generated randomization sequence, conducted by an independent individual. No significant baseline differences. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | Low; 78% in treatment group completed all lessons. Participants could not already be receiving CBT; required stable medication regimen. Psychotropic medication use not reported. | Some concerns; Two control group participants (10%) did not begin treatment and were not included in analyses. 9% in treatment group did not complete posttreatment questionnaire. All participants who started treatment were included in analyses. Missing data were handled with simple imputation of baseline scores. | High; Outcomes were self-report measures. Participants were not blind to group assignment and comparison condition was inactive. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; No protocol identified. | High
Spence 2014 | Some concerns; No details of randomization process provided. Non-exposure group was significantly older. | Low; From protocol it appears that participants were blinded. No reported deviations from intended intervention.. | Low.; High rates of treatment completion; all participants started at least 1 lesson. 73% int. vs. 79% control completed all lessons. | Low.; High rates of assessment completion. Analysis used appropriate methods to handle missing data. | High; Combination of clinician-administered and self-report measures that rely on participant report of symptoms. Participants were blind to group assignment and an active comparison condition was used, but assessors administering the CAPS were not blind to group assignment. Outcome measurement did not differ between groups. Validated outcome measures used. | Some concerns; Protocol includes PCL-C as an outcome measure; not reported in publication. | High
van Stolk-Cooke 2023 | Some concerns; No details of randomization process provided. Baseline differences not reported. | Low; Blinding of participants not feasible. No reported deviations from intended intervention. | High; Small percentage of patients used the app once. No information on co-interventions provided. | High; High rates of missing data. Analysis were appropriate to handle missing data, but given the high rates unclear how reliable it is. | Some concerns; Outcomes were self-report measures. Participants were not blind to group assignment, but active comparison condition was used. Outcome measurement did not differ between groups. Appears not all measures used were validated measures. | Low; Outcomes specified in protocol were reported. | High

Abbreviations. CBT=cognitive behavioral therapy; iCBT=internet-based cognitive behavioral therapy; ITT= intent to treat; LEC=Life Events Checklist for DSM-5; PANAS=The Positive and Negative Affect Schedule Scale; PCL= PTSD Checklist; PTCI=Posttraumatic Cognitions Inventory; PTSD=posttraumatic stress disorder; PCL-C=PTSD Checklist – Civilian Version; QoL=quality of life; TAU=treatment as usual; TIQ=therapy impact questionnaire; webPE=web-prolonged exposure.

## NONRANDOMIZED COMPARISON STUDIES (ROBINS-I)

Study Name or Author Year | Bias due to confounding | Selection bias | Bias in classification of interventions | Bias due to departures from intended interventions | Bias due to measurement of outcomes | Bias due to missing data | Bias in the selection of reported results | Overall risk of bias (Low, Moderate, Serious, Critical, No Information)
McCall 2023 | Low; Non-randomized preference trial. Prospective clients of an online iCBT service for public service personnel who reported clinically significant PTSD symptoms were offered choice of treatment. | Low; Intervention groups were clearly defined, prior to participants receiving treatment. | Unclear; 69% of participants accessed at least 4/5 lessons. Completion rates were similar for both groups. Excluded participants currently receiving another psychological treatment. No information on psychotropic medication use provided. | Unclear; Unclear whether outcome assessors were blind to group assignment, but outcomes were self-report measures and participants were not blind to group assignment. | Unclear; No significant differences between groups at baseline except for depression symptom severity. Unclear whether this difference was controlled for in analyses. | Unclear; Posttreatment assessments were completed by 65% of randomized participants. Participants who started the intervention were included in analyses (92%). Missing data was handled with multiple imputation. | Low; Primary outcomes and most secondary outcomes specified in protocol were reported. Publication is preliminary results of ongoing study and states that remaining data will be published in the future. | Unclear
Wiltsey Stirman 2021 | Low; Open trial participants were Talkspace clients with probable PTSD at intake. Only included individuals who completed PCL assessment at least twice in matched comparison. Comparison group was matched Talkspace clients who did not receive intervention who were seen in a similar timeframe and had similar baseline scores. | Low; Intervention groups were clearly defined. | Unclear; 64% of participants in CPT-Text intervention completed all 12 modules. Word count (estimate of engagement) was significantly higher for the TAU Talkspace group. Co-interventions not reported. | Unclear; Assessments were completed within Talkspace platform. Outcomes were self-report and could have been influenced by knowledge of the intervention received. Methods of outcome assessment were the same for both groups. | Unclear; Control group selected via propensity matching on baseline PTSD symptom severity and time in treatment. Matching did not take into account demographic characteristics. Demographics appear similar between groups, but race not reported for control group. Other potential confounding variables not examined. | Unclear; 82% of CPT-Text participants who had completed PCL assessments at least twice were matched and included in analyses. Method of handling missing data is not described. | Unclear; The study was not pre-registered. | Unclear

Abbreviations. CPT=cognitive processing therapy; iCBT=internet-based cognitive behavioral therapy; PCL=PTSD Checklist; PTSD=posttraumatic stress disorder; TAU=treatment as usual.

## PRE-POST STUDIES (ROBINS-I)

Study Name or Author Year | Bias due to confounding | Selection bias | Bias in classification of interventions | Bias due to departures from intended interventions | Bias due to measurement of outcomes | Bias due to missing data | Bias in the selection of reported results | Overall risk of bias (Low, Moderate, Serious, Critical, No Information)
Crenshaw 2023 | High; Examined differences between 2 study samples but did not account for potential confounders. | Low; Secondary analysis of data from 2 prospective studies; included all participants from those studies (except for 1 that did not start the study and wasn’t included in analyses for that study). | Low; Baseline and follow-up time points aligned with beginning and end of intervention; not influenced by outcome data. | Unclear; 33% did not complete the program. Treatment completers completed all treatment sessions. Co-interventions not reported. | Unclear; Assessments were completed online. Measures were self-report and participants were aware of receiving intervention. | Unclear; Analytic sample included all participants. Model-based imputation of missing data, but level of missing data was high (37% missing posttreatment assessment). | Low; All outcomes specified were reported, except for drug use, for which a rationale was provided. | High
Kuhn 2023 | High; Time trends not accounted for. No adjustment for confounders. | Low; Prospective study; selection of participants not based on characteristics observed after the start of the intervention. | Low; Baseline and follow-up time points aligned with beginning and end of intervention; not influenced by outcome data. | Unclear; Intervention was not completed by 27% of participants. Treatment completers completed all treatment sessions. Co-interventions not reported. | Unclear; Method of assessment not reported, but likely online consistent with other Couple HOPES study. Measures were self-report and participants were aware of receiving intervention. | Unclear; ITT analyses conducted (using all available data from all randomized participants) except for tertiary outcomes (which excluded 2 couples - 13%). Missing data was handled with model-based imputation. | Low; No indication of selective reporting. | High
Morland 2023 | High; Time trends not accounted for. No adjustment for confounders. | Low; Prospective study; selection of participants not based on characteristics observed after the start of the intervention. | Low; Baseline and follow-up time points aligned with beginning and end of intervention; not influenced by outcome data. | Unclear; Intervention was not completed by 27% of participants. Treatment completers completed all treatment sessions. Co-interventions not reported. | Unclear; Method of assessment not reported, but likely online consistent with other Couple HOPES study. Measures were self-report and participants were aware of receiving intervention. | Unclear; ITT analyses conducted (using all available data from all randomized participants) with the exception of tertiary outcomes (which excluded 2 couples - 13%). Missing data was handled with model-based imputation. | Low; No indication of selective reporting. | High

Abbreviations. ITT=intent to treat.