# UNDERWAY STUDIES

Citation
ACTRN12620000624987. Stepped care for adults with PTSD: a randomised controlled trial. Published online May 29, 2020. https://www.anzctr.org.au/Trial/Registration/TrialReview.aspx?ACTRN=12620000624987.
ACTRN12622000748718. A randomized control trial regarding the efficacy of an app series based on Eye Movement Desensitization and Reprocessing (EMDR) for Posttraumatic Stress Disorder (PTSD) symptoms.. Published online May 25, 2022. https://trialsearch.who.int/Trial2.aspx?TrialID=ACTRN12622000748718
ACTRN12622001099718. Guided Self-Help using Cognitive Processing Therapy for Posttraumatic Stress Disorder: a Randomized Controlled Trial. Published online August 8, 2022. https://www.anzctr.org.au/Trial/Registration/TrialReview.aspx?ACTRN=12622001099718
ChiCTR2200058408. Efficacy and Mechanisms of Mobile Application-delivered Acceptance and Commitment Therapy for Posttraumatic Stress Disorder. Published online April 9, 2022. https://www.chictr.org.cn/showproj.html?proj=165803
ChiCTR2200059328. The efficacy of online EMDR for PTSD patients: a randomized controlled single-blind trial. Published online April 28, 2022. http://www.chictr.org.cn/showproj.aspx?proj=167602
DRKS00030285. Cognitive Bias Modification for Interpretation (CBM-I) Training for Anxiety Disorders (Study A) and Posttraumatic Stress Disorder (Study B): a Randomized-Controlled Smartphone-App Based Trial. 2022.
DRKS00031290. Internet-based treatment for adult crime victims with posttraumatic stress disorder: a clinical trial. 2023.
ISRCTN16806208. A randomised controlled trial of therapist-assisted online psychological therapies for post-traumatic stress disorder. Published online 2018. https://trialsearch.who.int/Trial2.aspx?TrialID=ISRCTN16806208
NCT02400710. Clinician-Supported PTSD Coach vs. Self-Managed PTSD Coach. Published online March 16, 2015. https://clinicaltrials.gov/study/NCT02400710?term=NCT02400710&rank=1&tab=table
NCT03154151. Online Therapy for Posttraumatic Stress Symptoms in WTC Responders. Published online May 12, 2017. https://clinicaltrials.gov/study/NCT03154151?term=NCT03154151&limit=10&rank=1&tab=table
NCT03593772. Mission Reconnect- Delivering a Mobile and Web Based Self Directed Complementary and Integrative Health Program to Veterans and Their Partners to Manage Pain and PTSD. Published online May 22, 2018. https://clinicaltrials.gov/study/NCT03593772?term=NCT03593772&limit=10&rank=1
NCT04000217. Written Versus Verbal Brief Cognitive Behavioral Exposure Therapy. Published online June 24, 2019. https://clinicaltrials.gov/study/NCT04000217?term=NCT04000217&limit=10&rank=1
NCT04035304. Online and Mobile Mindfulness Intervention to Reduce Distress. Published online July 24, 2019. https://clinicaltrials.gov/study/NCT04035304
NCT04058795. PTSD Mobile App for Cancer Survivors. Published online August 14, 2019. https://clinicaltrials.gov/study/NCT04058795?term=NCT04058795&rank=1
NCT04306809. iACT for PTSD and Chronic Pain: a Development Pilot Series. Published online February 20, 2020. https://clinicaltrials.gov/study/NCT04306809?term=NCT04306809&limit=10&rank=1&tab=table
NCT04501328. A Randomized Controlled Trial of Coaching Into Care With VA-CRAFT to Promote Veteran Engagement in PTSD Care. Published online August 6, 2020. https://classic.clinicaltrials.gov/ct2/show/NCT04501328?term=NCT04501328&draw=2&rank=1
NCT04763681. Couple HOPES (Helping Overcome PTSD and Enhance Satisfaction). Published online February 13, 2021. https://clinicaltrials.gov/study/NCT04763681?term=NCT04763681&limit=10&rank=1
NCT04769986. Mobile Mindfulness for Alcohol Use and PTSD Among Veterans. Published online February 17, 2021. https://clinicaltrials.gov/study/NCT04769986?term=NCT04769986&limit=10&rank=1&tab=table
NCT04959695. Evaluation of the PE Coach Mobile Application Among Veterans With PTSD. Published online May 3, 2021. https://clinicaltrials.gov/study/NCT04959695?term=NCT04959695&limit=10&rank=1
NCT05037175. Telehealth 2.0: evaluating Effectiveness and Engagement Strategies for CPT-Text for PTSD. Published online August 31, 2021. https://clinicaltrials.gov/study/NCT05037175?term=NCT05037175&limit=10&rank=1
NCT05147948. iACT for PTSD and Chronic Pain. Published online October 8, 2021. https://clinicaltrials.gov/study/NCT05147948?term=NCT05147948&limit=10&rank=1&tab=table
NCT05372042. CBT Texts for PTSD & Hazardous Drinking (Project Better). Published online May 5, 2022. https://clinicaltrials.gov/study/NCT05372042?term=NCT05372042&limit=10&rank=1
NCT05564663. Testing a PTSD m-Health Intervention to Improve Alcohol Treatment Outcomes. Published online September 28, 2022. https://clinicaltrials.gov/study/NCT05564663?term=NCT05564663&rank=1&tab=table
NCT05700578. Evaluation of a Novel Behavior Change Intervention for Posttraumatic Stress. Published online January 17, 2023. https://clinicaltrials.gov/study/NCT05700578?term=NCT05700578&rank=1&tab=table
NCT05758987. Blended Treatment för PTSD: a New Format of Computer-Assisted Trauma-Focused Cognitive Behavioral Therapy. Published online February 15, 2023. https://clinicaltrials.gov/study/NCT05758987?term=NCT05758987&rank=1
NCT05934162. Efficacy of Internet-delivered Cognitive-behavior Therapy for PTSD. Published online June 26, 2023. https://clinicaltrials.gov/study/NCT05934162?term=NCT05934162&rank=1
Ehlers A, Wild J, Warnock-Parkes E, . A randomised controlled trial of therapist-assisted online psychological therapies for posttraumatic stress disorder (STOP-PTSD): trial protocol. Trials. 2020;21(1):355.32326954
Godfrey L, Cloitre M, Elwy R, Fortuna L, Fuchs C, Valentine S. Study protocol for a hybrid 1 effectiveness-implementation trial of Brief Skills Training in Affective and Interpersonal Regulation (brief STAIR) and web-administered STAIR (webSTAIR) for posttraumatic stress disorder in integrated primary care. Contemporary Clinical Trials. 2023;131.
Haun JN, Ballistrea LM, Melillo C, . A Mobile and Web-Based Self-Directed Complementary and Integrative Health Program for Veterans and Their Partners (Mission Reconnect): Protocol for a Mixed-Methods Randomized Controlled Trial. JMIR research protocols. 2019;8(5):e13666. doi:10.2196/13666 31094345
Kroener J, Greiner A, Sosic-Vasic Z. Cognitive bias modification for interpretation (CBM-I) for post-traumatic stress disorder: study protocol of an app-based randomised controlled trial. BMJ Open. 2023;13(2):e069228. doi:10.1136/bmjopen-2022-069228
Kunovski I, Donker T, Driessen E, Cuijpers P, Andersson G, Sijbrandij M. Internet-delivered cognitive behavioral therapy for posttraumatic stress disorder in international humanitarian aid workers: Study protocol. Internet Interventions. 2017;10(101631612):23–28. doi:10.1016/j.invent.2017.09.002 30135749
Lebeaut A, Pedersen ER, Francis DJ, Zvolensky MJ, Vujanovic AA. Evaluation of an integrated personalized feedback intervention for hazardous drinkers with elevated anxiety sensitivity and PTSD symptoms: Protocol for a randomized controlled trial. Contemporary Clinical Trials Communications. 2023;32(101671157):101088.36824449
McLean CP, Miller ML, Gengler R, Henderson J, Sloan DM. The efficacy of written exposure therapy versus imaginal exposure delivered online for posttraumatic stress disorder: Design of a randomized controlled trial in Veterans. Contemporary Clinical Trials. 2020;91(101242342):105990.32184198
Smith SK, Somers TJ, Kuhn E, . A SMART approach to optimizing delivery of an mHealth intervention among cancer survivors with posttraumatic stress symptoms. Contemporary Clinical Trials. 2021;110(101242342):106569.34536584
Sripada RK, Smith K, Walters HM, . Testing adaptive interventions to improve PTSD treatment outcomes in Federally Qualified Health Centers: Protocol for a randomized clinical trial. Contemporary Clinical Trials. 2023;129(101242342):107182. doi:10.1016/j.cct.2023.107182.37044157