# STUDIES EXCLUDED DURING FULL-TEXT SCREENING

Citation | Exclude Reason
ACTRN12606000401550. The efficacy of an Internet-based therapy (Interapy) for posttraumatic stress: a randomized controlled trial. Published online September 13, 2006. https://www.anzctr.org.au/Trial/Registration/TrialReview.aspx?ACTRN=12606000401550 | Ineligible publication type
ACTRN12610000988055. The PTSD Program: a randomized controlled trial of an internet based education program for post-traumatic stress disorder. Published online November 16, 2010. https://www.anzctr.org.au/Trial/Registration/TrialReview.aspx?ACTRN=12610000988055 | Ineligible publication type
ACTRN12611000951954. Sino-Swiss Internet-based intervention for Posttraumatic Stress Disorder project. Published online May 9, 2011. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-02433400/full | Ineligible setting
ACTRN12611000989943. A comparison of Internet-based Cognitive Behavioural Therapy for Posttraumatic Stress Disorder with and without exposure: a randomized controlled trial. Published online September 16, 2011. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01835812/full | Ineligible publication type
ACTRN12616000956404. Internet-based intervention for Posttraumatic Stress Disorder (PTSD) in soldiers: exploring mechanisms of treatment outcome. Published online July 20, 2016. https://www.anzctr.org.au/Trial/Registration/TrialReview.aspx?id=370924 | Ineligible publication type
Allen AR, Newby JM, Smith J, Andrews G. Internet-based cognitive behavioural therapy (iCBT) for posttraumatic stress disorder versus waitlist control: study protocol for a randomised controlled trial. Trials. 2015;16(101263253):544.26628268 | Ineligible publication type
Alon Y, Azriel O, Pine D, Bar-Haim Y. A randomized controlled trial of supervised remotely-delivered attention bias modification for posttraumatic stress disorder. Psychological Medicine. 2022. | Ineligible intervention
Bahena S. Efficacy of a mobile application among a sample of veterans with symptoms of post-traumatic stress disorder. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2016;77(2-B(E)):No-Specified. | Full text unavailable
Barrett MC. Beta-testing of an interactive multimedia computer program of exposure therapy for PTSD. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2019;80(8-B(E)):No-Specified. | Ineligible comparator
Bartel A. Examining change in objective and subjective neurocognitive performance following a randomized online trauma intervention. 2021;82. | Full text unavailable
Bauer A, Amspoker AB, Fletcher TL, . A Resource Building Virtual Care Programme: improving symptoms and social functioning among female and male rural veterans. European journal of psychotraumatology. 2021;12(1):1860357.34025913 | Ineligible intervention
Bedford LA, Dietch JR, Taylor DJ, Boals A, Zayfert C. Computer-Guided Problem-Solving Treatment for Depression, PTSD, and Insomnia Symptoms in Student Veterans: A Pilot Randomized Controlled Trial. Behavior therapy. 2018;49(5):756–767.30146142 | Ineligible population
Belleville G, Lebel J, Ouellet MC, . Resilient - An online multidimensional treatment to promote resilience and better sleep: a randomized controlled trial. 2019;64:S214–S215. | Ineligible publication type
Belleville G, Ouellet M-C, Bekes V, . Efficacy of a Therapist-Assisted Self-Help Internet-Based Intervention Targeting PTSD, Depression, and Insomnia Symptoms After a Disaster: A Randomized Controlled Trial. Behavior therapy. 2023;54(2):230–246.36858756 | Ineligible population
Benight CC, Shoji K, Yeager CM, Weisman P, Boult TE. Predicting Change in Posttraumatic Distress Through Change in Coping Self-Efficacy After Using the My Trauma Recovery eHealth Intervention: Laboratory Investigation. JMIR mental health. 2018;5(4):e10309.30497992 | Ineligible population
Berkel DN. A randomized controlled trial of a brief online mindfulness intervention for PTSD and chronic pain. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2022;83(11-B):No-Specified. | Full text unavailable
Bisson JI, Kitchiner NJ, Lewis C, Roberts NP. Guided, internet-based interventions for post-traumatic stress disorder. The lancet Psychiatry. 2023;10(8):577–579.37479336 | Ineligible publication type
Bomyea J. Evaluating the effect of a novel cognitive training program on ptsd symptoms. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2015;75(12-B(E)):No-Specified. | Full text unavailable
Bragesjo M, Arnberg FK, Sarnholm J, Olofsdotter Lauri K, Andersson E. Condensed internet-delivered prolonged exposure provided soon after trauma: A randomised pilot trial. Internet interventions. 2021;23(101631612):100358.33384946 | Ineligible population
Brief DJ, Rubin A, Keane TM, . Web intervention for OEF/OIF veterans with problem drinking and PTSD symptoms: a randomized clinical trial. Journal of consulting and clinical psychology. 2013;81(5):890–900.23875821 | Ineligible population
Bruner V, Gore K, DeDeyn J, Jaffer A, Litz B, Bryant R. A therapist-guided internet-based self-management approach to post-traumatic stress after military events. 2004. | Full text unavailable
Buckheit KA, Possemato K, Kuhn E. An exploration of alcohol use and mechanisms of change during PTSD treatment in primary care. 2023;47:348. | Full text unavailable
Cernvall M, Sveen J, Bergh Johannesson K, Arnberg F. A pilot study of user satisfaction and perceived helpfulness of the Swedish version of the mobile app PTSD Coach. European journal of psychotraumatology. 2018;9(Suppl 1):1472990.29805783 | Ineligible population
Cloitre M, Amspoker AB, Fletcher TL, . Comparing the Ratio of Therapist Support to Internet Sessions in a Blended Therapy Delivered to Trauma-Exposed Veterans: Quasi-experimental Comparison Study. JMIR mental health. 2022;9(4):e33080.35475777 | Ineligible intervention
Craske MG, Rose RD, Lang A, . Computer-assisted delivery of cognitive behavioral therapy for anxiety disorders in primary-care settings. Depression and anxiety. 2009;26(3):235–242.19212970 | Ineligible intervention
Creech S, Pulverman C, Shin M, . An open trial to test participant satisfaction with and feasibility of a computerized intervention for women veterans with sexual trauma histories seeking primary care treatment. Violence Against Women. 2020;27(3–4):597–614.31896315 | Ineligible population
Damon M. The impact of a low-intensity couples intervention on emotional intimacy in veterans with PTSD and their partners. Dissertation Abstracts International Section A: Humanities and Social Sciences. 2020;81(2-A):No-Specified. | Full text unavailable
Dannhaus LA. Mindfulness-based stress reduction in veterans: A variation on a pilot study. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2019;80(3-B(E)):No-Specified. | Full text unavailable
Dillon KH, Medenblik AM, Mosher TM, Elbogen EB, Morland LA, Beckham JC. Using Interpretation Bias Modification to Reduce Anger in Veterans with Posttraumatic Stress Disorder: A Pilot Study. Journal of traumatic stress. 2020;33(5):857–863.32516517 | Ineligible intervention
DRKS00016931. Internet-based therapy for physicians with post-traumatic stress. Published online 2019. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01972960/full | Full text unavailable
DRKS00017749. Self-Management and PTSD: Assessing Usability and Applicability of CoachPTBS as well as HCC over time. Published online January 11, 2019. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-02067323/full | Full text unavailable
Dumarkaite A, Truskauskaite-Kuneviciene I, Andersson G, Kazlauskas E. The Effects of Online Mindfulness-Based Intervention on Posttraumatic Stress Disorder and Complex Posttraumatic Stress Disorder Symptoms: A Randomized Controlled Trial With 3-Month Follow-Up. Frontiers in psychiatry. 2022;13(101545006):799259.35432020 | Ineligible outcome
Dumarkaite A, Truskauskaite-Kuneviciene I, Andersson G, Mingaudaite J, Kazlauskas E. Effects of Mindfulness-Based Internet Intervention on ICD-11 Posttraumatic Stress Disorder and Complex Posttraumatic Stress Disorder Symptoms: a Pilot Randomized Controlled Trial. Mindfulness. 2021;12(11):2754–2766.34539930 | Ineligible population
Duran EP, Hemanny C, Vieira R, . A Randomized Clinical Trial to Assess the Efficacy of Online-Treatment with Trial-Based Cognitive Therapy, Mindfulness-Based Health Promotion and Positive Psychotherapy for Post-Traumatic Stress Disorder during the COVID-19 Pandemic: A Study Protocol. International journal of environmental research and public health. 2022;19(2). | Ineligible intervention
Ehlers A, Wild J, Warnock-Parkes E, . Therapist-assisted online psychological therapies differing in trauma focus for post-traumatic stress disorder (STOP-PTSD): a UK-based, single-blind, randomised controlled trial. The Lancet Psychiatry. 2023;10(8):608–622. doi:10.1016/S2215-0366(23)00181-5 37479341 | Ineligible intervention
Elbogen EB, Dennis PA, Van Voorhees EE, . Cognitive rehabilitation with mobile technology and social support for veterans with TBI and PTSD: a randomized clinical trial. Journal of Head Trauma Rehabilitation. 2018. | Ineligible intervention
Elbogen EB, Dennis PA, Van Voorhees EE, . Cognitive Rehabilitation With Mobile Technology and Social Support for Veterans With TBI and PTSD: A Randomized Clinical Trial. The Journal of head trauma rehabilitation. 2019;34(1):1–10.30169439 | Ineligible intervention
Elledge BD. The efficacy of online eye movement desensitization and reprocessing (EMDR)-informed therapy for clients with post traumatic stress disorder (PTSD) symptoms. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2022;83(7-B):No-Specified. | Full text unavailable
Engel CC, Litz B, Magruder K, Gore K, Harper Cordova E, Yeager D. Randomized Trial of A Web-Based Nurse-Assisted PTSD Self-Management Intervention for Primary Care: study Design and Status. 2009. | Ineligible publication type
Enggasser JL, Livingston NA, Ameral V, . Public implementation of a web-based program for veterans with risky alcohol use and PTSD: A RE-AIM evaluation of VetChange. Journal of substance abuse treatment. 2021;122(kai, 8500909):108242.33509419 | Ineligible population
Fitzpatrick S, Wagner AC, Crenshaw AO, . Initial outcomes of couple HOPES: A guided online couple intervention for PTSD and relationship enhancement. Internet Interventions. 2021;25(101631612):100423. doi:10.1016/j.invent.2021.100423 34401382 | Ineligible outcome
Gawlytta R, Knaevelsrud C, Niemeyer H, Bottche M, Scherag A, Rosendahl J. Internet-based cognitive-behavioral writing therapy reduces post-traumatic stress after intensive care in patients and their spouses: first results of the REPAIR trial. 2019;47:S54. | Ineligible publication type
Gawlytta R, Niemeyer H, Bottche M, Scherag A, Knaevelsrud C, Rosendahl J. Internet-based cognitive-behavioural writing therapy for reducing post-traumatic stress after intensive care for sepsis in patients and their spouses (REPAIR): study protocol for a randomised-controlled trial. BMJ open. 2017;7(2):e014363. | Ineligible publication type
Hallenbeck HW, Jaworski BK, Wielgosz J, . PTSD Coach Version 3.1: A Closer Look at the Reach, Use, and Potential Impact of This Updated Mobile Health App in the General Public. JMIR mental health. 2022;9(3):e34744.35348458 | Ineligible outcome
Hirai M, Skidmore ST, Clum GA, Dolma S. An Investigation of the Efficacy of Online Expressive Writing for Trauma-Related Psychological Distress in Hispanic Individuals. Behavior Therapy. 2012;43(4):812–824. doi:10.1016/j.beth.2012.04.006 23046783 | Ineligible population
Interian A, Kline A, Perlick D, . Randomized controlled trial of a brief Internet-based intervention for families of Veterans with posttraumatic stress disorder. Journal of rehabilitation research and development. 2016;53(5):629–640. doi:10.1682/JRRD.2014.10.0257 27898154 | Ineligible outcome
ISRCTN13697710. A study of trauma-focused online guided self help versus trauma-focused cognitive behavioural therapy for post-traumatic stress disorder. Published online 2016. https://www.isrctn.com/ISRCTN13697710?q=ISRCTN13697710&filters=&sort=&offset=1&totalResults=1&page=1&pageSize=10 | Ineligible publication type
Jain S. Treating posttraumatic stress disorder via the Internet: does therapeutic alliance matter? JAMA. 2011;306(5):543–544.21813433 | Ineligible publication type
Johnson SS, Levesque DA, Broderick LE, Bailey DG, Kerns RD. Pain Self-Management for Veterans: Development and Pilot Test of a Stage-Based Mobile-Optimized Intervention. JMIR medical informatics. 2017;5(4):e40.29042341 | Ineligible population
Jung F, Rohr S, Konig HH, Kersting A, Riedel-Heller SG. HELP@APP : study design for the development and evaluation of a self-help app fortraumatized Syrian refugees in Germany. 2019;81(8–9):672. | Ineligible publication type
Kim S, Lee K. Development and evaluation of an online mental health program for traumatized female college students: A randomized controlled trial. Archives of psychiatric nursing. 2023;43(6yr, 8708534, 8708535):118–126.37032005 | Ineligible intervention
Kirk MA, Taha B, Dang K, . A Web-Based Cognitive Behavioral Therapy, Mindfulness Meditation, and Yoga Intervention for Posttraumatic Stress Disorder: Single-Arm Experimental Clinical Trial. JMIR mental health. 2022;9(2):e26479.34499613 | Ineligible intervention
Knaevelsrud C. Effects of an Internet-based Intervention for Posttraumatic Stress Disorder. 2011. | Ineligible publication type
Knaevelsrud C, Maercker A. Long-term effects of an internet-based treatment for posttraumatic stress. Cognitive behaviour therapy. 2010;39(1):72–77.19675958 | Ineligible population
Lange A, Schrieken B, van de Ven J-P, . “Interapy”: The effects of a short protocolled treatment of posttraumatic stress and pathological grief through the Internet. Behavioural and Cognitive Psychotherapy. 2000;28(2):175–192. | Ineligible population
Lange A, van de Ven JP, Schrieken B, Emmelkamp PM. Interapy, treatment of posttraumatic stress through the Internet: a controlled trial. Journal of behavior therapy and experimental psychiatry. 2001;32(2):73–90.11764063 | Ineligible population
Lange A, van de Ven JP, Schrieken BA, Bredeweg B, Emmelkamp PM. Internet-mediated, protocol-driven treatment of psychological dysfunction. Journal of telemedicine and telecare. 2000;6(1):15–21.10824385 | Ineligible population
Lehavot K, Litz B, Millard SP, Hamilton AB, Sadler A, Simpson T. Study adaptation, design, and methods of a web-based PTSD intervention for women Veterans. Contemporary clinical trials. 2017;53(101242342):68–79.27940187 | Ineligible study design
Lerner JA. Internet-based assessment and treatment for posttraumatic stress disorder among motor vehicle accident survivors. 2007;68(3-B):1932. | Full text unavailable
Lerner JA. Internet-based assessment and treatment for posttraumatic stress disorder among motor vehicle accident survivors [dissertation] 2007. | Full text unavailable
Litz BT, Williams L, Wang J, Bryant R, Engel CC, Jr. A Therapist-Assisted Internet Self-Help Program for Traumatic Stress. Professional Psychology: Research and Practice. 2004;35(6):628–634. | Ineligible publication type
Livingston NA, Mahoney CT, Ameral V, . Changes in alcohol use, PTSD hyperarousal symptoms, and intervention dropout following veterans’ use of VetChange. Addictive behaviors. 2020;107(2gw, 7603486):106401.32272356 | Ineligible population
McLean CL, Ruork AK, Ramaiya MK, Fruzzetti AE. Feasibility and initial impact of single-session internet-delivered acceptance vs change skills for emotions for stress- and trauma-related problems: a randomized controlled trial. Behavioural and cognitive psychotherapy. 2023;51(5):443–458.37288653 | Ineligible population
McLean CP, Rauch SAM, Foa EB, . Design of a randomized controlled trial examining the efficacy and biological mechanisms of web-prolonged exposure and present-centered therapy for PTSD among active-duty military personnel and veterans. Contemporary clinical trials. 2018;64(101242342):41–48.29128649 | Ineligible publication type
Mitchell H-R, Smith SK, Gebert R, Applebaum AJ. Mobile cognitive behavioral therapy for posttraumatic stress: Diving back in after hematopoietic stem cell transplant. Psychooncology. 2022;31(10):1802–1805.36050923 | Ineligible study design
Monson CM, Wagner AC, Crenshaw AO, . An uncontrolled trial of couple HOPES: A guided online couple intervention for PTSD and relationship enhancement. Journal of family psychology. 2022;36(6):1036–1042. doi:10.1037/fam0000976 35266773 | Ineligible outcome
NCT01410721. Neural Markers and Rehabilitation of Executive Functioning in Veterans with Traumatic Brain Injury and Posttraumatic Stress Disorder. Published online August 3, 2011. https://clinicaltrials.gov/study/NCT01410721?tab=table | Ineligible publication type
NCT01474057. DElivery of Self Training and Education for Stressful Situations-Primary Care Version. Published online March 26, 2010. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01533942/full | Ineligible publication type
NCT01554839. The Family of Heroes: an Evaluation of an Online Educational Tool. Published online March 5, 2012. https://clinicaltrials.gov/study/NCT01554839?term=NCT01554839&rank=1 | Ineligible publication type
NCT01581983. Mindfulness Meditation Format Pilot Study. Published online April 7, 2012. https://clinicaltrials.gov/study/NCT01581983?term=NCT01581983&rank=1 | Ineligible publication type
NCT01678196. Helping Families Help Veterans With PTSD and Alcohol Abuse: an RCT of VA-CRAFT. Published online August 29, 2012. https://clinicaltrials.gov/study/NCT01678196?term=NCT01678196&rank=1 | Ineligible publication type
NCT01694316. Use of a Novel Neuroplasticity-based Neurobehavioral Intervention for PTSD. Published online September 27, 2012. https://classic.clinicaltrials.gov/ct2/show/NCT01694316?term=NCT01694316&draw=2&rank=1 | Ineligible publication type
NCT01710943. Web-based CBT for Recent Veterans Experiencing Problems With Trauma Symptoms or Alcohol/Drug Use. Published online October 19, 2012. https://classic.clinicaltrials.gov/ct2/show/NCT01710943 | Ineligible publication type
NCT02445196. PTSD Coach App Evaluation. Published online May 15, 2015. https://classic.clinicaltrials.gov/ct2/show/NCT02445196?term=NCT02445196&draw=2&rank=1 | Ineligible publication type
NCT02486692. Pilot Evaluation of AboutFace: novel Peer Education Resource for Veterans. Published online July 1, 2015. https://classic.clinicaltrials.gov/ct2/show/NCT02486692?term=NCT02486692&draw=2&rank=1 | Ineligible publication type
NCT02486705. Evaluation of PTSD Family Coach, a Mobile Phone App for Family Members of Individuals With PTSD. Published online July 1, 2015. https://classic.clinicaltrials.gov/ct2/show/NCT02486705 | Ineligible publication type
NCT02685358. An RCT of a Primary Care-Based PTSD Intervention: clinician-Supported PTSD Coach. Published online February 12, 2016. https://clinicaltrials.gov/study/NCT02685358?term=NCT02685358&rank=1 | Ineligible publication type
NCT02766296. Emotional Working Memory Training for Veterans With PTSD Symptoms. Published online May 4, 2016. https://clinicaltrials.gov/study/NCT02766296?term=NCT02766296&rank=1 | Ineligible publication type
NCT02777294. Evaluation of Web-Based CBT for Rape Victims. Published online May 19, 2016. https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01558386/full | Ineligible publication type
NCT02917447. Evaluation of Web-Based CBT for Women Veterans With PTSD. Published online September 23, 2016. https://clinicaltrials.gov/study/NCT02917447?term=NCT02917447&limit=10&rank=1 | Ineligible publication type
NCT02929979. Cognitive Remediation for Alcohol Use Disorder and Posttraumatic Stress Disorder. Published online September 28, 2016. https://clinicaltrials.gov/study/NCT02929979?term=NCT02929979&limit=10&rank=1 | Ineligible publication type
NCT02954146. Mobile Health Application for Family and Behavioral Health Provider Communication. Published online October 24, 2016. https://clinicaltrials.gov/study/NCT02954146?term=NCT02954146&rank=1 | Ineligible publication type
NCT02956902. A Smartphone Intervention with Telemedicine Support for Management of Post-traumatic Stress Disorder: a Randomized Trial. Published online November 6, 2016. https://classic.clinicaltrials.gov/ct2/show/NCT02956902 | Ineligible publication type
NCT02986152. Cancer Distress Coach Mobile App Trial. Published online December 6, 2016. https://clinicaltrials.gov/study/NCT02986152?term=NCT02986152&limit=10&rank=1 | Ineligible population
NCT03196999. Remotely Resolving Psychological Stress (Remote RePS). Published online June 20, 2017. https://clinicaltrials.gov/study/NCT03196999?term=NCT03196999&limit=10&rank=1&tab=table | Ineligible publication type
NCT03199742. Evaluation of a Mobile Phone App for Veterans With PTSD. Published online June 20, 2017. https://clinicaltrials.gov/study/NCT03199742?term=NCT03199742&limit=10&rank=1 | Ineligible publication type
NCT03208738. Pilot Evaluation of the VetChange Mobile App for Veterans With PTSD Who Engage in Problem Drinking. Published online July 11, 2017. https://clinicaltrials.gov/study/NCT03208738?term=NCT03208738&limit=10&rank=1 | Ineligible publication type
NCT03906240. Pilot Study Testing a Web-Based Moral Elevation Intervention for Veterans With PTSD and Moral Injury. Published online March 27, 2019. https://clinicaltrials.gov/study/NCT03906240?term=NCT03906240&limit=10&rank=1&tab=table | Ineligible publication type
NCT04094922. PTSD Coach Sweden: evaluating a Self-help Mobile App for Posttraumatic Stress in a Community Sample. Published online September 17, 2019. https://clinicaltrials.gov/study/NCT04094922?term=NCT04094922&limit=10&rank=1 | Ineligible publication type
NCT04155736. Testing a Self-Management App for Symptoms of Posttraumatic Stress. Published online October 30, 2019. https://clinicaltrials.gov/study/NCT04155736?term=NCT04155736&limit=10&rank=1 | Ineligible publication type
NCT04231578. Couple HOPES (Helping Overcome PTSD and Enhance Satisfaction). Published online January 18, 2020. https://classic.clinicaltrials.gov/ct2/show/NCT04231578 | Ineligible publication type
NCT04333667. Effectiveness of Mindfulness-based Internet Intervention Still Me. Published online March 31, 2020. https://clinicaltrials.gov/study/NCT04333667?term=NCT04333667&limit=10&rank=1 | Ineligible publication type
NCT04771767. Combined Ketamine and eCBT Intervention for PTSD. Published online November 19, 2020. https://clinicaltrials.gov/study/NCT04771767?term=NCT04771767&limit=10&rank=1 | Ineligible intervention
NCT05569915. Project QueST: queer Survivors of Trauma. Published online October 3, 2022. https://clinicaltrials.gov/study/NCT05569915?term=NCT05569915&rank=1&tab=table | Ineligible population
Nollett C, Lewis C, Kitchiner N, . Pragmatic RAndomised controlled trial of a trauma-focused guided self-help Programme versus InDividual trauma-focused cognitive Behavioural therapy for post-traumatic stress disorder (RAPID): trial protocol. BMC psychiatry. 2018;18(1):77.29580220 | Ineligible publication type
NTR5065. The effectiveness of a mobile app in reducing of post-traumatic stress symptoms. Published online February 24, 2015. https://www.onderzoekmetmensen.nl/en/trial/29192 | Ineligible publication type
NTR5758. Addition of the EMD app in PTSD treatment. Published online February 26, 2016. https://www.onderzoekmetmensen.nl/en/trial/23716 | Ineligible publication type
NTR6912. Addition of the SUPPORT Coach in PTSD treatment. Published online December 22, 2017. https://www.onderzoekmetmensen.nl/en/trial/28504 | Ineligible publication type
Owen JE, Jaworski BK, Kuhn E, Makin-Byrd KN, Ramsey KM, Hoffman JE. mHealth in the Wild: Using Novel Data to Examine the Reach, Use, and Impact of PTSD Coach. JMIR mental health. 2015;2(1):e7.26543913 | Ineligible population
PACTR202108609876315. Internet-based treatment of PTSD. Published online June 5, 2020. https://pactr.samrc.ac.za/TrialDisplay.aspx?TrialID=11016 | Ineligible publication type
Parish MB, Apperson M, Yellowlees PM. Engaging U.S. veterans with PTSD in online therapy. Psychiatric services (Washington, DC). 2014;65(5):697. | Ineligible publication type
Philipp-Muller AE, Reshetukha T, Vazquez G, . Combining Ketamine and Internet-Based Cognitive Behavioral Therapy for the Treatment of Posttraumatic Stress Disorder: Protocol for a Randomized Controlled Trial. JMIR research protocols. 2021;10(7):e30334.34092549 | Ineligible publication type
Possemato K, Johnson E, Barrie K, . A Randomized Clinical Trial of Clinician-Supported PTSD Coach in VA Primary Care Patients. Journal of general internal medicine. 2023;38(Suppl 3):905–912. | Ineligible intervention
Possemato K, Ouimette P, Geller Pamela A. Internet-based expressive writing for kidney transplant recipients: effects on posttraumatic stress and quality of life. 2010;16(1):49–54. | Ineligible population
Putois B, Peter-Derex L, Leslie W, Braboszcz C, El-Hage W, Bastuji H. Internet-Based Intervention for Posttraumatic Stress Disorder: Using Remote Imagery Rehearsal Therapy to Treat Nightmares. Psychotherapy and psychosomatics. 2019;88(5):315–316.31284286 | Ineligible intervention
Reger GM, Smolenski D, Williams R, . Design and methods of a randomized controlled trial evaluating the effects of the PE Coach mobile application on prolonged exposure among veterans with PTSD. Contemporary clinical trials. 2023;127(101242342):107115.36758935 | Ineligible intervention
Reitsma L, Boelen PA, de Keijser J, Lenferink LIM. Self-guided online treatment of disturbed grief, posttraumatic stress, and depression in adults bereaved during the COVID-19 pandemic: A randomized controlled trial. Behaviour research and therapy. 2023;163(9kp, 0372477):104286.36906949 | Ineligible population
Rice VJ, Liu B, Schroeder PJ. Impact of In-Person and Virtual World Mindfulness Training on Symptoms of Post-Traumatic Stress Disorder and Attention Deficit and Hyperactivity Disorder. Military medicine. 2018;183(suppl_1):413–420.29635610 | Ineligible intervention
Rohr S, Jung FU, Pabst A, . A Self-Help App for Syrian Refugees With Posttraumatic Stress (Sanadak): Randomized Controlled Trial. JMIR mHealth and uHealth. 2021;9(1):e24807.33439140 | Ineligible population
Sagaltici E, Cetinkaya M, Kocamer Sahin S, Gulen B, Karaman S. Recent Traumatic Episode Protocol EMDR Applied Online for COVID-19-Related Symptoms of Turkish Health Care Workers Diagnosed with COVID-19-Related PTSD: A Pilot Study. Alpha psychiatry. 2022;23(3):121–127.36425782 | Ineligible intervention
Scharff FB, Lau ME, Riisager LHG, . The PTSD help app in a Danish PTSD population: research protocol of a randomized controlled feasibility trial. Pilot and feasibility studies. 2020;6(101676536):92. doi:10.1186/s40814-020-00633-x 32617173 | Ineligible publication type
Schroedter B. Mindfulness-based stress management for veterans (pilot study) [dissertation] 2016. | Full text unavailable
Schroedter B. Mindfulness-based stress management for veterans (pilot study). Dissertation Abstracts International: Section B: The Sciences and Engineering. 2017;78(5-B(E)):No-Specified. | Full text unavailable
Schuman DL, Lawrence KA, Boggero I, . A Pilot Study of a Three-Session Heart Rate Variability Biofeedback Intervention for Veterans with Posttraumatic Stress Disorder. Applied psychophysiology and biofeedback. 2023;48(1):51–65.36331685 | Ineligible intervention
Seal KH. Enhancing Cognitive Function and Reintegration in Iraq and Afghanistan Veterans With PTSD Using Computer-Based Cognitive Training. 2012. | Full text unavailable
Short NA, Boffa JW, Raudales AM, Schmidt NB. A randomized clinical trial investigating perceived burdensomeness as a mediator of brief intervention effects on posttraumatic stress symptoms. Journal of affective disorders. 2020;262(h3v, 7906073):344–349.31740111 | Ineligible population
Stockton H, Joseph SA, Hunt NC. Expressive writing and posttraumatic growth: an internet-based study. Traumatology. 2014;20(2):75–83. | Ineligible population
Thorisdottir AS, Asmundson G. Internet-delivered cognitive processing therapy for individuals with a history of bullying victimization: a randomized controlled trial. Cognitive behaviour therapy. 2022;51(2):143–169.34184620 | Ineligible population
UMIN000026518. Single arm no-randomized open trial on feasibility and efficacy of internet-based acute treatment / recovery program for sexual assaulted victims with PTSD. Published online March 15, 2017. https://center6.umin.ac.jp/cgi-open-bin/ctr_e/ctr_view.cgi?recptno=R000030454 | Ineligible publication type
Van Voorhees BW, Gollan J, Fogel J. Pilot study of Internet-based early intervention for combat-related mental distress. Journal of rehabilitation research and development. 2012;49(8):1175–1190.23341310 | Ineligible population
Wallace T, Morris J. A Technology Supported mRehab Intervention for Stress Management in TBI and PTSD: pilot Study Results. 2019;100(10):e37–e38. | Ineligible publication type
Wallace T, Morris JT, Glickstein R, Anderson RK, Gore RK. Implementation of a Mobile Technology-Supported Diaphragmatic Breathing Intervention in Military mTBI With PTSD. The Journal of head trauma rehabilitation. 2022;37(3):152–161.35703895 | Ineligible intervention
Xu W, Wang J, Wang Z, . Web-based intervention improves social acknowledgement and disclosure of trauma, leading to a reduction in posttraumatic stress disorder symptoms. Journal of health psychology. 2016;21(11):2695–2708.25934590 | Ineligible setting
Evaluating the Effect of a Novel Cognitive Training Program on PTSD Symptoms. 2014. https://www.proquest.com/dissertations-theses/evaluating-effect-novel-cognitive-training/docview/1645187802/se-2?accountid=147085 | Full text unavailable