# SEARCH STRATEGIES

Search Date: 10/04/23 | | Search Statement | Results
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to October 03, 2023 | 1 | Stress Disorders, Post-Traumatic/ or (((post-trauma* or posttrauma) adj3 (disorder* or neuros* or psychos* or stress* or symptom*)) or PTSD).ti,ab,kw. | 61613
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to October 03, 2023 | 2 | exp Telemedicine/ or Therapy, Computer Assisted/ or Internet/ or Internet-Based Intervention/ or exp Cell Phone/ or Mobile Applications/ or (electronic health or ehealth or e-health or digital health or mobile health or mhealth or m-health or ecounsel* or e-counsel* or etherap* or e-therap* or computer* or phone* or mobile* or internet* or online* or web-based or web-deliver* or app or apps or app-based or app-deliver* or application-based or application-deliver* or text or texting or text-based or text-deliver* or asynchronous).ti,ab,kw. | 1050854
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to October 03, 2023 | 3 | 1 and 2 | 4141
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to October 03, 2023 | 4 | (adolescen* or child* or infant* or pediatric* or paediatric* or PICU).ti,ab,kw. | 2385079
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to October 03, 2023 | 5 | 3 not 4 | 3447
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to October 03, 2023 | 6 | limit 5 to English language | 3391
PsycINFO; 1967 to September Week 4 2023 | 1 | Posttramatic Stress Disorder/ or (((post-trauma* or posttrauma) adj3 (disorder* or neuros* or psychos* or stress* or symptom*)) or PTSD).ti,ab,id. | 59114
PsycINFO; 1967 to September Week 4 2023 | 2 | exp Computer Assisted Therapy/ or Internet/ or exp Mobile Devices/ or exp Mobile Applications/ or (electronic health or ehealth or e-health or digital health or mobile health or mhealth or m-health or ecounsel* or e-counsel* or etherap* or e-therap* or computer* or phone* or mobile* or internet* or online* or web-based or web-deliver* or app or apps or app-based or app-deliver* or application-based or application-deliver* or text or texting or text-based or text-deliver* or asynchronous).ti,ab,id. | 390142
PsycINFO; 1967 to September Week 4 2023 | 3 | 1 and 2 | 3854
PsycINFO; 1967 to September Week 4 2023 | 4 | (adolescen* or child* or infant* or pediatric* or paediatric* or PICU).ti,ab,id. | 959997
PsycINFO; 1967 to September Week 4 2023 | 5 | 3 not 4 | 3086
PsycINFO; 1967 to September Week 4 2023 | 6 | limit 5 to English language | 2902
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 1 | MeSH descriptor: [Stress Disorders, Post-Traumatic] this term only | 3701
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 2 | (((post-trauma* or posttrauma*) NEAR/3 (disorder* or neuros* or psychos* or stress* or symptom*)) or PTSD):ti,ab,kw | 8502
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 3 | #1 or #2 | 8502
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 4 | MeSH descriptor: [Telemedicine] explode all trees | 4293
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 5 | MeSH descriptor: [Therapy, Computer-Assisted] this term only | 1480
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 6 | MeSH descriptor: [Internet] this term only | 5193
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 7 | MeSH descriptor: [Internet-Based Intervention] this term only | 568
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 8 | MeSH descriptor: [Cell Phone] explode all trees | 3166
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 9 | MeSH descriptor: [Mobile Applications] this term only | 1601
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 10 | (electronic health or ehealth or e-health or digital health or mobile health or mhealth or m-health or ecounsel* or e-counsel* or etherap* or e-therap* or computer* or phone* or mobile* or internet* or online* or web-based or web-deliver* or app or apps or app-based or app-deliver* or application-based or application-deliver* or text or texting or text-based or text-deliver* or asynchronous):ti,ab,kw | 139626
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 11 | {or #4-#10} | 141452
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 12 | #3 and #11 | 1407
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 13 | (adolescen* or child* or infant* or pediatric* or paediatric* or PICU):ti,ab,kw | 338152
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 14 | #11 not #12 | 1106
CCRCT: Cochrane Central Register of Controlled Trials; Issue 10 of 12, October 2023 | 15 | limit 14 to English language | 1103
PTSDPubs | 1 | MAINSUBJECT.EXACT.EXPLODE(“PTSD”) or TITLE(((post-trauma* or posttrauma) NEAR/3 (disorder* or neuros* or psychos* or stress* or symptom*)) or PTSD) or ABSTRACT(((post-trauma* or posttrauma) NEAR/3 (disorder* or neuros* or psychos* or stress* or symptom*)) or PTSD) | 48425
PTSDPubs | 2 | MAINSUBJECT.EXACT(“Telemedicine”) OR MAINSUBJECT.EXACT(“Computer Assisted Psychotherapy”) OR TITLE(electronic health or ehealth or e-health or digital health or mobile health or mhealth or m-health or ecounsel* or e-counsel* or etherap* or e-therap* or computer* or phone* or mobile* or internet* or online* or web-based or web-deliver* or app or apps or app-based or app-deliver* or application-based or application-deliver* or text or texting or text-based or text-deliver* or asynchronous) OR ABSTRACT(electronic health or ehealth or e-health or digital health or mobile health or mhealth or m-health or ecounsel* or e-counsel* or etherap* or e-therap* or computer* or phone* or mobile* or internet* or online* or web-based or web-deliver* or app or apps or app-based or app-deliver* or application-based or application-deliver* or text or texting or text-based or text-deliver* or asynchronous) | 7060
PTSDPubs | 3 | [S1] and [S2] | 5042
PTSDPubs | 4 | MAINSUBJECT.EXACT.EXPLODE(“Children”) or MAINSUBJECT.EXACT(“Adolescents”) OR TITLE(adolescen* or child* or infant* or pediatric* or paediatric* or PICU) or ABSTRACT (adolescen* or child* or infant* or pediatric* or paediatric* or PICU) | 18496
PTSDPubs | 5 | [S3] not [S4] | 4167
PTSDPubs | 6 | limit 3 to English language | 4111
PTSDPubs | 7 | limit to peer-reviewed studies, dissertations, and reports | 3060
| | Total | 10456
| | Total after deduplication | 7507