# ABBREVIATIONS TABLE

Abbreviation: Definition
CAPS: Clinician-Administered PTSD Scale
CAPS-5: Clinician-Administered PTSD Scale for DSM-5
CBT: Cognitive behavioral therapy
CI: Confidence interval
Couple HOPES: Couple Helping Overcome PTSD and Enhance Satisfaction
DoD: Department of Defense
DSM-5: Diagnostic and Statistical Manual of Mental Disorders - version 5
IES: Impact of Events Scale
IES-R: Impact of Events Scale - Revised
iCBT: Internet-based cognitive behavioral therapy
KQ: Key Question
MINI: Mini International Neuropsychiatric Interview
NRT: Non-randomized trial
OECD: Organisation for Economic Co-operation and Development
OR: Odds ratio
PC-PTSD: Primary Care PTSD Screen
PCL-5: PTSD Checklist for DSM-5
PCL-C: PTSD Checklist – Civilian version
PCL-M: PTSD Checklist – Military version
PCL-S: PTSD Checklist – Specific version
PDS: Posttraumatic Stress Diagnostic Scale
PE: Prolonged exposure
PI: Prediction interval
PSS-I: Posttraumatic Symptom Scale – Interview version
PSS-SR: Posttraumatic Symptom Scale – Self-report
PTS: Posttraumatic stress
PTSD: Posttraumatic stress disorder
RCT: Randomized controlled trial
SMD: Standardized mean difference
SMS: Short messaging service
SOE: Strength of evidence
TAU: Treatment as usual
TES: Traumatic Event Scale
UK: United Kingdom
VA: Department of Veterans Affairs
VA-CRAFT: Veterans Affairs – Community Reinforcement and Family Training
VHA: Veterans Health Administration
WET: Written exposure therapy