# References

1 Marshall K, Gowing L, Ali R, Le Foll B. Pharmacotherapies for cannabis dependence. The Cochrane database of systematic reviews. 2014(12):CD008940.25515775
2 Pacek LR, Mauro PM, Martins SS. Perceived risk of regular cannabis use in the United States from 2002 to 2012: differences by sex, age, and race/ethnicity. Drug and alcohol dependence. 2015;149:232–244.25735467
3 Legalizing marijuana and the new science of weed (video) [press release]. https://www.acs.org/content/acs/en/pressroom/newsreleases/2015/march/legalizing-marijuana-and-the-new-science-of-weed-video.html2015.
4 Keyhani S, Steigerwald S, Ishida J, . Risks and Benefits of Marijuana Use: A National Survey of U.S. Adults. Ann Intern Med. 2018;169(5):282–290.30039154
5 Laprevote V, Schwan R, Schwitzer T, Rolland B, Thome J. Is There a Place for Off-Label Pharmacotherapy in Cannabis Use Disorder? A Review on Efficacy and Safety. Current pharmaceutical design. 2015;21(23):3298–3305.26088109
6 Danovitch I, Gorelick DA. State of the art treatments for cannabis dependence. The Psychiatric clinics of North America. 2012;35(2):309–326.22640758
7 Hasin DS, Kerridge BT, Saha TD, . Prevalence and Correlates of DSM-5 Cannabis Use Disorder, 2012-2013: Findings from the National Epidemiologic Survey on Alcohol and Related Conditions–III. American Journal of Psychiatry. 2016;173(6):588–599.26940807
8 American Psychiatric Association. Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Publishing. 2013.
9 Blanco C, Hasin DS, Wall MM, . Cannabis Use and Risk of Psychiatric Disorders: Prospective Evidence From a US National Longitudinal Study. JAMA Psychiatry. 2016;73(4):388–395.26886046
10 Bonn-Miller MO, Harris AH, Trafton JA. Prevalence of cannabis use disorder diagnoses among veterans in 2002, 2008, and 2009. Psychological services. 2012;9(4):404–416.22564034
11 Kondo K, Ayers C, Morasco B, O’Neil M, Nugent S, Kansagara D. Pharmacotherapy for the treatment of cannabis use disorder: a systematic review. PROSPERO 2018 CRD42018108064 Available from: http://www.crd.york.ac.uk/PROSPERO/display_record.php?ID=CRD42018108064.
12 McGowan J, Sampson M, Salzwedel DM, Cogo E, Foerster V, Lefebvre C. PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. Journal of clinical epidemiology. 2016;75:40–46.27005575
13 Treadwell JR, Singh S, Talati R, McPheeters ML, Reston JT. AHRQ Methods for Effective Health Care. In: A Framework for “Best Evidence” Approaches in Systematic Reviews. Rockville (MD): Agency for Healthcare Research and Quality (US); 2011.
14 Higgins JP, Altman DG, Gotzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. BMJ (Clinical research ed). 2011;343:d5928.
15 Higgins J, Green S. Cochrane Handbook for Systematic Reviews of Interventions Version 5.1.0. 2011; http://handbook.cochrane.org/. Accessed March 24, 2017.
16 Review Manager (RevMan) [Computer program]. Version 5.3. Copenhagen: The Nordic Cochrane Centre, The Cochrane Collaboration, 2014.
17 Berkman N, Lohr K, Ansari M, . Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. 2013; http://www.effectivehealthcare.ahrq.gov/ehc/products/457/1752/methods-guidance-grading-evidence-131118.pdf. Accessed December 28, 2016.
18 McRae-Clark AL, Baker NL, Gray KM, Killeen T, Hartwell KJ, Simonian SJ. Vilazodone for cannabis dependence: A randomized, controlled pilot trial. The American journal on addictions. 2016;25(1):69–75.26685701
19 Levin FR, Mariani J, Brooks DJ, . A randomized double-blind, placebo-controlled trial of venlafaxine-extended release for co-occurring cannabis dependence and depressive disorders. Addiction. 2013;108(6):1084–1094.23297841
20 Cornelius JR, Bukstein OG, Douaihy AB, . Double-blind fluoxetine trial in comorbid MDD-CUD youth and young adults. Drug Alcohol Depend. 2010;112(1–2):39–45.20576364
21 Carpenter KM, McDowell D, Brooks DJ, Cheng WY, Levin FR. A preliminary trial: double-blind comparison of nefazodone, bupropion-SR, and placebo in the treatment of cannabis dependence. Am J Addict. 2009;18(1):53–64.19219666
22 Weinstein AM, Miller H, Bluvstein I, . Treatment of cannabis dependence using escitalopram in combination with cognitive-behavior therapy: a double-blind placebo-controlled study. The American journal of drug and alcohol abuse. 2014;40(1):16–22.24359507
23 Penetar DM, Looby AR, Ryan ET, Maywalt MA, Lukas SE. Bupropion reduces some of the symptoms of marihuana withdrawal in chronic marihuana users: a pilot study. Substance abuse : research and treatment. 2012;6:63–71.22879754
24 Schnell T, Koethe D, Krasnianski A, . Ziprasidone versus clozapine in the treatment of dually diagnosed (DD) patients with schizophrenia and cannabis use disorders: a randomized study. The American journal on addictions. 2014;23(3):308–312.24628830
25 McRae-Clark AL, Baker NL, Gray KM, . Buspirone treatment of cannabis dependence: A randomized, placebo-controlled trial. Drug and alcohol dependence. 2015;156:29–37.26386827
26 McRae-Clark AL, Carter RE, Killeen TK, . A placebo-controlled trial of buspirone for the treatment of marijuana dependence. Drug Alcohol Depend. 2009;105(1–2):132–138.19699593
27 Johnston J, Lintzeris N, Allsop DJ, . Lithium carbonate in the management of cannabis withdrawal: a randomized placebo-controlled trial in an inpatient setting. Psychopharmacology. 2014;231(24):4623–4636.24880749
28 Levin FR, McDowell D, Evans SM, . Pharmacotherapy for marijuana dependence: a double-blind, placebo-controlled pilot study of divalproex sodium. Am J Addict. 2004;13(1):21–32.14766435
29 McRae-Clark AL, Carter RE, Killeen TK, Carpenter MJ, White KG, Brady KT. A placebo-controlled trial of atomoxetine in marijuana-dependent individuals with attention deficit hyperactivity disorder. Am J Addict. 2010;19(6):481–489.20958842
30 Levin FR, Mariani JJ, Brooks DJ, Pavlicova M, Cheng W, Nunes EV. Dronabinol for the treatment of cannabis dependence: a randomized, double-blind, placebo-controlled trial. Drug Alcohol Depend. 2011;116(1–3):142–150.21310551
31 Levin FR, Mariani JJ, Pavlicova M, . Dronabinol and lofexidine for cannabis use disorder: A randomized, double-blind, placebo-controlled trial. Drug and alcohol dependence. 2016;159:53–60.26711160
32 Hill KP, Palastro MD, Gruber SA, . Nabilone pharmacotherapy for cannabis dependence: A randomized, controlled pilot study. The American journal on addictions. 2017;26(8):795–801.28921814
33 Trigo JM, Soliman A, Quilty LC, . Nabiximols combined with motivational enhancement/cognitive behavioral therapy for the treatment of cannabis dependence: A pilot randomized clinical trial. PloS one. 2018;13(1):e0190768.29385147
34 Allsop DJ, Copeland J, Lintzeris N, . Nabiximols as an agonist replacement therapy during cannabis withdrawal: a randomized clinical trial. JAMA psychiatry. 2014;71(3):281–291.24430917
35 Miranda R, Jr., Treloar H, Blanchard A, . Topiramate and motivational enhancement therapy for cannabis use among youth: a randomized placebo-controlled pilot study. Addiction biology. 2017;22(3):779–790.26752416
36 Mason BJ, Crean R, Goodell V, . A proof-of-concept randomized controlled study of gabapentin: effects on cannabis use, withdrawal and executive function deficits in cannabis-dependent adults. Neuropsychopharmacology. 2012;37(7):1689–1698.22373942
37 Gray KM, Sonne SC, McClure EA, . A randomized placebo-controlled trial of N-acetylcysteine for cannabis use disorder in adults. Drug and alcohol dependence. 2017;177:249–257.28623823
38 Gray KM, Carpenter MJ, Baker NL, . A double-blind randomized controlled trial of N-acetylcysteine in cannabis-dependent adolescents. Am J Psychiatry. 2012;169(8):805–812.22706327
39 Institute TSR, Abuse NIoD. Pharmacological Treatment of Comorbid Alcohol and Marijuana Withdrawal and Dependence. In: https://ClinicalTrials.gov/show/NCT02210195; 2014.
40 Sherman BJ, Baker NL, McRae-Clark AL. Effect of oxytocin pretreatment on cannabis outcomes in a brief motivational intervention. Psychiatry research. 2017;249:318–320.28152465