# Acknowledgments

This topic was developed in response to a nomination by Dr. Dominick DePhilippis, Education Coordinator at Philadelphia CESATE, in conjunction with Dr. Karen Drexler, National Mental Health Program Director, Substance Use Disorders for the Office of Mental Health Services for the purpose of examining the effectiveness and best practices for pharmacotherapy for cannabis use disorder. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodological approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Dominick DePhilippis, PhD
  Education Coordinator, Philadelphia CESATE
  Office of Mental Health Services and Philadelphia CESATE
- Karen Drexler, MD
  National Mental Health Program Director, Substance Use Disorders
  Office of Mental Health Services

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- James McKay, PhD
  Professor of Psychology in Psychiatry, University of Pennsylvania
  Director, Philadelphia CESATE
- Eric Hawkins, PhD
  Associate Professor, Department of Psychiatry & Behavioral Sciences, University of Washington
  Associate Director Seattle CESATE
  VA Puget Sound Health Care System
- Andrew Saxon, MD
  Professor and Director, Addiction Psychiatry Residency Program, Department of Psychiatry & Behavioral Sciences, University of Washington
  Director, Seattle CESATE
  VA Puget Sound Health Care System
- Kendall Browne, PhD
  Core Investigator, Center of Excellence in Substance Addiction Treatment and Education (CESATE), Corporal Michael J. Crescenz VA Medical Center; Philadelphia, PA
  Associate Director for Training and Education, Center of Excellence in Substance Addiction
  Treatment and Education (CESATE), VA Puget Sound Health Care System; Seattle, WA
  Acting Assistant Professor, Department of Psychiatry & Behavioral Health, University of Washington
- Kipling Bohnert, PhD
  Assistant Professor of Psychiatry, University of Michigan Medical School
  Core Investigator, VA Ann Arbor HSR&D Center for Clinical Management Research (CCMR)
- Tony P. George, MD
  Professor and Chair of Addiction Psychiatry, University of Toronto
  Clinical Director, Schizophrenia program at the U of T Centre for Addiction and Mental Health
- Kevin M. Gray, MD
  Professor of Addiction Sciences, Medical University of South Carolina
- Mark A. Ilgen, PhD
  Professor, Department of Psychiatry
  Director, University of Michigan Addiction Treatment Services
  Associate Director for Adult Research, Addiction Center
  Research Investigator, Center for Clinical Management Research, Ann Arbor VA Healthcare System

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.