# Results

We reviewed a total of 983 studies. After title and abstract review, 59 met inclusion criteria. Upon full-text review, we included a total of 11 RCTs, plus an additional 12 from a previous systematic review,^1^ for a total of 23 RCTs. The 7 RCTs examined in Key Question 2 were also included in Key Question 1 (see Figure 2; Quality assessment is presented in Appendix D).

Figure 2 Literature Flow Diagram

*All 7 KQ 2 studies were also included in KQ 1.

## KEY QUESTION 1 What are the benefits and harms of pharmacotherapy for cannabis use disorder?

We identified 23 RCTs that addressed Key Question 1. Twelve trials examined psychopharmacological interventions, 5 trials examined cannabinoids, 2 trials examined anticonvulsants, 2 trials examined N-acetylcysteine, 1 trial examined aprepitant, and 1 trial examined oxytocin.

### Psychopharmacology

We identified 12 trials examining psychopharmacological interventions for the treatment of cannabis use disorder. Trials examined antidepressants (ie, escitalopram, fluoxetine, bupropion, nefazodone, venlafaxine, vilazodone), antipsychotics (ie, clozapine, ziprasidone), buspirone, mood stabilizers (ie, divalproex, lithium), and atomoxetine. Overall, studies found that antidepressants as a class were less effective than placebo for the achievement of abstinence (moderate SOE). There was no difference between antidepressants (moderate SOE) or buspirone (low SOE) and placebo in reducing overall cannabis use or retention in treatment. We found low strength evidence of no difference from placebo for antidepressants or buspirone on harms. Antidepressant medications did not impact secondary outcomes (low SOE). Findings for all other psychopharmacotherapies and drug/outcome combinations were either insufficient or were not identified in the current literature.

#### Antidepressants: Escitalopram, Fluoxetine, Bupropion, Nefazodone, Venlafaxine, Vilazodone

We identified 4 low-ROB RCTs^18–21^ and 2 high-ROB RCTs^22,23^ examining the use of antidepressants for the treatment of cannabis use disorder. Trials comparing escitalopram^22^ and bupropion and nefazodone^21^ to placebo found no difference for the achievement of abstinence. However, 1 trial found that significantly fewer subjects who received venlafaxine achieved abstinence.^19^

Two RCTs found no difference from placebo in reduction of cannabis use associated with fluoxetine^20^ or vilazodone.^18^ However, 1 RCT found significantly higher urinary THC levels in the second half of the study among subjects randomized to venlafaxine compared to those receiving placebo.^19^

No trial examining antidepressants found a significant difference in study retention, harms, or withdrawal symptoms compared to placebo. Studies generally had high rates of attrition, with the exception of a trial comparing fluoxetine to placebo^20^ in subjects aged 14-25, which was provided in combination with contingency management, cognitive behavioral therapy (CBT), and motivational enhancement therapy (MET). This trial had improved retention relative to other trials.

The secondary outcomes that were assessed varied widely by study. Findings were largely not significantly different between antidepressants and placebo. The exceptions were more missed medication doses of nefazodone compared to bupropion and placebo,^21^ and greater reduction on a single subscale of cannabis craving (purposefulness) associated with vilazodone.^18^

Interestingly, in the 3 trials examining the effect on depressive symptomology, none identified a benefit of antidepressant medication from placebo (see below for more detail).^19,20,22^

Across all antidepressants studied, we found moderate strength evidence that the achievement of abstinence is less likely in subjects receiving antidepressants than placebo (3 RCTs, N=291; combined RR=0.49, 95% CI [0.30-0.83]; see Figure 3). Because 1 RCT had 2 active treatment arms (nefazodone and bupropion),^21^ we combined the active arms in a sensitivity analysis to examine the effect of using the same control group twice when each drug was compared separately with placebo in meta-analysis. Upon combining the active treatment arms, findings were consistent (combined RR=0.46, 95% CI [0.27-0.78]). In addition, we found moderate strength evidence that antidepressants have no benefit for reducing cannabis use (2 RCTs found no difference from placebo, 1 RCT found greater reduction with placebo)^18–20^, and that antidepressants are no different from placebo for retaining participants in treatment (6 RCTs, N=429, combined RR=0.95, 95% CI [0.85-1.07]; see Figure 4). One trial reporting retention outcomes was only 4 weeks in duration.^23^ We performed a sensitivity analysis without the trial and found no difference in overall findings (combined RR=0.93, 95% CI [0.81 to 1.07]).

There is low strength evidence that antidepressant medications did not impact study dropout due to adverse events, and that randomization to antidepressant medications did not result in improvement on secondary outcome measures. Although the RCTs assessed different secondary outcomes, we found no consistent impact of antidepressant medications on measures of craving for cannabis, time to first THC-negative urinalysis (UA), symptoms of depression or anxiety, cognitive effects, or medication adherence (see Tables 2, 3, and 5 and the Conclusions Table for more detail).

Of the 6 RCTs that evaluated an antidepressant medication among those with comorbid major depressive disorder (MDD), 4 also assessed differences in depressive symptom reduction by treatment.^19,20,22,23^ At baseline, subjects in 2 RCTs fell in the severe range,^19,22^ subjects in 1 RCT fell in the mild to moderate range,^20^ and in 1 RCT subjects were within non-clinical ranges.^23^ Among subjects with severe depression at baseline, randomization to escitalopram^22^ or venlafaxine^19^ did not result in clinically significant reductions in depressive symptoms and there were no statistically significant reductions relative to those randomized to placebo.^19,22^ Among subjects in the mild to moderate range at baseline, subjects randomized to both fluoxetine and placebo experienced significant reductions in depressive symptoms over the course of the study, though there were no between-group differences detected.^20^ In the RCT which included participants with subclinical depressive symptoms at baseline, neither participants randomized to bupropion or placebo had significant changes in symptom severity, nor was there a difference in symptom reduction when comparing the 2 groups.^23^

Figure 3 Number of patients who achieve 2+ week abstinence in trials comparing antidepressants versus placebo for cannabis use disorder

Figure 4 Number of patients who completed treatment in trials comparing antidepressants versus placebo for cannabis use disorder

#### Antipsychotics: Clozapine, Ziprasidone

There is insufficient evidence examining the effectiveness of antipsychotic medications to treat cannabis use disorder. We identified 1 high-ROB head-to-head RCT^24^ comparing ziprasidone and clozapine (N=30) in adults with both cannabis use disorder and a psychotic spectrum disorder. Findings indicated no difference between groups on cannabis use or study retention. Results suggest that clozapine may be associated with more adverse events (specifically hypersalivation), and that ziprasidone may be associated with better drug tolerance and psychotherapy compliance. Positive (psychotic) symptoms decreased significantly for both groups, with a stronger decline in clozapine (P=0.05). Ziprasidone was associated with more emergency therapy sessions (P=0.022), and higher group therapy attendance (P=0.024; see Tables 2, 3 and 5, and the Conclusions Table for more detail).

#### Anxiolytics: Buspirone

One low-ROB RCT^25^ and 1 unclear-ROB RCT^26^ provide data about the efficacy of buspirone for the treatment of CUD. We found low strength evidence that buspirone is no better than placebo for study retention (2 RCTs, N=268, RR=0.92, 95% CI [0.71-1.19]; Figure 5). In intent-to-treat analyses, neither study identified statistically significant differences in the likelihood of negative UA results over the course of the study (low SOE). There is low strength evidence that buspirone treatment does not increase adverse events. Findings were insufficient to form conclusions about any differences between buspirone and placebo on secondary outcomes (see Tables 2, 3, and 5, and the Conclusions Table).

Figure 5 Number of patients who completed treatment in trials comparing buspirone versus placebo for cannabis use disorder

#### Mood Stabilizers: Divalproex, Lithium

One low-ROB RCT^27^ (lithium) and 1 high-ROB RCT^28^ (divalproex) provide insufficient evidence from which to form conclusions about the use of mood stabilizers for the treatment of cannabis use disorder. Trials found no difference between divalproex or lithium versus placebo for abstinence or the frequency or quantity of cannabis use. We performed a meta-analysis to examine the effect of mood stabilizers on study retention and found no difference from placebo (RR=1.07, 95% CI [0.79 – 1.44]; see Figure 6). Related to withdrawal symptoms, divalproex did not differ from placebo for craving or irritability.^28^ Lithium was similar to placebo in reported withdrawal severity. However, lithium was more effective for attenuating nightmares, loss of appetite, and stomachaches.^27^ Neither RCT found a difference in study retention as compared to placebo. Findings also suggested better rates of medication compliance with placebo versus divalproex, and no difference between lithium and placebo for severity of dependence or cannabis-related problems (see Tables 2, 3, and 5, and the Conclusions Table).^28^

Figure 6 Number of patients who completed treatment in trials comparing mood stabilizers versus placebo for cannabis use disorder

#### Cognitive-enhancing: Atomoxetine

One unclear-ROB RCT^29^ provides insufficient evidence for the use of atomoxetine for the treatment of cannabis use disorder. The trial compared 100 mg of atomoxetine to placebo, along with contingency management (CM) and motivational enhancement therapy (MET) in subjects with comorbid attention deficit hyperactivity disorder (ADHD). Findings indicated no difference between atomoxetine and placebo on cannabis use, treatment retention, or dropout from treatment due to adverse events. Subjects who received atomoxetine experienced greater ADHD improvement on the Clinical Global Impressions improvement scale (CGI-I; P=0.022) and a greater decline in ADHD symptoms in weeks 1-4. There was no difference from placebo on the CGI severity scale (CGI-S), and no difference in ADHD symptom improvement after week 4 (see Tables 2, 3, and 5, and the Conclusions Table).

### Cannabinoids: Dronabinol, Nabilone, Nabiximols

Included studies examined dronabinol, a pharmaceutically prepared synthetic THC,^30,31^ nabilone, an FDA-approved synthetic cannabinoid,^32^ and nabiximols, a pharmaceutically prepared nasal spray of 27mg/ml of THC and 25mg of cannabidiol (CBD).^33,34^

Two low-ROB RCTs^30,34^ and 3 unclear-ROB RCTs^31–33^ examined the use of cannabinoids for the treatment of cannabis use disorder. A small RCT (N=18) compared nabilone to placebo and found no difference on any outcome of interest.^32^ Two trials compared dronabinol to placebo and found no difference for the achievement of abstinence (RR=1.07, 95% CI [0.65-1.76]; see Figure 7), reduction in cannabis use, cannabis craving, or harms. Findings were mixed for the effect of dronabinol on withdrawal symptoms and study retention. Two trials compared nabiximols to placebo. Findings on the effect of nabiximols on withdrawal symptoms were mixed, with 1 of 2 RCTs reporting better outcomes with treatment than placebo (see Tables 2 and 3).^33,34^

Across cannabinoids as a class, we found low strength evidence that dronabinol specifically has no effect on the achievement of abstinence, low strength evidence that cannabinoids are no different than placebo for reducing cannabis use, and moderate strength evidence that they are similar to placebo for study retention (5 RCTs, N=387; combined RR=1.06, 95% CI [0.89-1.25]; see Figure 8). One trial reporting retention outcomes was only 4 weeks in duration;^34^ we performed a sensitivity analysis without this trial and found no difference in overall findings (4 RCTs, N=336; combined RR=1.04, 95% CI [0.87-1.24]). There is low strength evidence that cannabinoids may reduce withdrawal symptoms, and that they do not increase harms. Although findings were consistent across studies regarding treatment dropout s due to adverse events, we downgraded strength of evidence due to high attrition and lack of clarity related to reasons for dropout. Findings for secondary outcomes are insufficient to draw conclusions (see Table 5 and the Conclusions Table).

Figure 7 Number of patients who achieved abstinence in trials of cannabinoids versus placebo for cannabis use disorder

Figure 8 Number of patients who completed treatment in trials comparing cannabinoids versus placebo for cannabis use disorder

### Anticonvulsants: Gabapentin, Topiramate

Two small, unclear-ROB RCTs^35,36^ provide evidence for the use of gabapentin^36^ and topiramate^35^ for the treatment of cannabis use disorder. Findings indicated better retention associated with both gabapentin and topiramate. Subjects receiving gabapentin (N=50), but not topiramate, significantly decreased their cannabis use as compared to those receiving placebo. In addition, gabapentin was associated with a decrease in depressive symptoms and better neurocognitive performance, whereas subjects receiving topiramate experienced poorer depressive and neurocognitive outcomes than those receiving placebo. Gabapentin also performed better than placebo for cannabis withdrawal symptoms and a range of secondary outcomes (see Tables 2 and 3). Across anticonvulsants as a class, we found low strength evidence for improved treatment retention over placebo, and insufficient evidence for all other outcomes of interest (see Table 5 and the Conclusions Table).

### Glutamatergic Modulator: N-acetylcysteine

Two low-ROB RCTs^37,38^ examine the effectiveness of the glutamatergic modulating dietary supplement N-acetylcysteine (NAC) versus placebo for the treatment of cannabis use disorder. One RCT examined adults,^37^ and the other examined adolescents and young adults (ages 13-21).^38^ Neither trial found a difference in the reduction of cannabis use versus placebo (see Figure 9), study retention (see Figure 10), harms, or medication adherence. The RCT examining adolescents and young adults found a non-significant trend towards 2-week end of trial abstinence favoring NAC (see Tables 2 and 3).^38^

Across trials examining NAC, we found moderate strength evidence of no difference from placebo for the reduction of cannabis use, study retention, and medication adherence. Although both RCTs (N=418) reported no difference in dropouts from treatment due to adverse events, high attrition in both trials call into question reasons for dropout; therefore, we determined the evidence to be low-strength. There was also low strength evidence of no difference in the frequency of serious adverse events by group (see Table 5 and the Conclusions Table).

Figure 9 Number of negative-UAs in trials comparing N-acetylcysteine versus placebo for cannabis use disorder

Events = Number of negative-UAs based on proportion of ITT total; Total = Maximum number of intended UA specimens (ITT) based on total randomized patients, number of weeks, and frequency of collection.

Figure 10 Number of patients who completed treatment in trials comparing N-acetylcysteine versus placebo for cannabis use disorder

### Antiemetic/Antinauseant: Aprepitant

One small (N=20), unpublished RCT^39^ of aprepitant versus placebo provides insufficient evidence from which to form conclusions for the use of aprepitant for the treatment of concurrent cannabis and alcohol use disorders. There was a greater change in cannabis use from Week 0 to Week 8 with aprepitant; however, statistical significance was not determined. Only 60% of participants were retained in the aprepitant group as compared to 100% in the placebo group (see Tables 2, 3, and 5, and the Conclusions Table for more detail).

### Hormone: Oxytocin

One small (N=16) high-ROB RCT^40^ of adults with cannabis use disorder provides insufficient evidence from which to draw conclusions on the use of the hormone oxytocin for the treatment of cannabis use disorder. The trial examined whether the use of oxytocin prior to motivational enhancement therapy (MET) sessions resulted in better outcomes. Although findings are insufficient, the trial found no difference between groups on cannabis use for oxytocin versus placebo (see Tables 2, 3, and 5, and the Conclusion Table for more detail).

Table 2 Trials of pharmacotherapies for treating primary outcomes of cannabis use disorder

Setting; N Randomized; # of Sites; Mean follow-up; Population; Comorbidity | N, T vs C; Treatment dose & duration; Concomitant treatment; UA frequency | Population^*^; Male %; Age, mean (SD); Race %; SES | Treatment vs Comparator | | | Risk of bias
Setting; N Randomized; # of Sites; Mean follow-up; Population; Comorbidity | N, T vs C; Treatment dose & duration; Concomitant treatment; UA frequency | Population^*^; Male %; Age, mean (SD); Race %; SES | Abstinence, Lapse or Relapse: ≥2 weeks, N (%) and/or longest consecutive period, mean (SD) | Overall cannabis use | Retention in treatment | Risk of bias
PSYCHOPHARMACOTHERAPIES
Selective Serotonin Reuptake Inhibitors (SSRIs): Escitalopram, Fluoxetine
Weinstein, 2014^22^; N=52; Single site (Israel); 23-week follow-up; DSM IV Cannabis Dependence; Comorbid Major Depressive Disorder | 26 vs 26; Escitalopram 10 mg 9 wks; 60 min group CBT 1x/wk + MET.; Instructed to stop cannabis use after 4 weeks.; UA: every 2 wks after wk 4 | 75% male; Age: 32.71 (6.8); Race: NR; Education: 12.42 (2) | 3/26 vs 7/26; No difference in “persistent” UA(-) (P=0.77). | NR | 26 (50%) completed study: 10/26 (38.5%) vs 16/26 (61.5%); (P=0.43; analysis NR in study) | High
Cornelius, 2010^20^; N=70; Single site (US); 12-week follow-up; DSM IV CUD^**^ or HAM-D ‡ 15; Comorbid Major Depressive Disorder | 34 vs 36; Fluoxetine 10mg first 2 weeks/ 20mg wks 3-12; 12 wks; CBT (9 therapy sessions over 12 wks) + MET; CM: $20 for each assessment visit; UA: frequency unspecified | 61.4% male; Age: 21 (2.4); Race: 55.7% White, 37.1 AA/Black, 7.1% Mixed; SES: NR | NR | No difference in days used (based on self-report). | 64 (91.4%) completed study: 31/34 (91.2%) vs 33/36 (91.7%); No difference | Low
Other Antidepressants: Bupropion, Nefazodone, Venlafaxine, Vilazodone
Carpenter, 2009^21^; N=106; 2 Sites (US); 13-week follow-up; DSM IV Cannabis Dependence | 40 vs 36 vs 30; Bupropion 300 mg/day vs Nefazodone 600 mg/day (or MTD) vs PBO; CM for attendance ($5/visit; 26 visits) Individual coping skills-based CBT; UA: 2x/week | 76.4% male; Age: 32(10) years; Race: 34% White, 27% AA/Black, 28% Hispanic; Education: 42.5% high school or less; Employment: 9.4% Unemployed | 4/40 vs 8/36 vs 7/30; No difference in 3+ week abstinence (P=0.58) | No difference in end-of-study UA(-); (P=0.17) | 46 (43.4%) completed study: 18/40 (45%) vs 14/36 (38.9%) vs 14/30 (46.6%); No difference (P=0.55) | Low
Penetar, 2012^23^; N=22; Single site (US); 4-week follow-up; DSM-IV Cannabis Abuse or Dependence. | 10 vs 12; 7-day baseline period. Bupropion 300mg/day; Instructed to stop cannabis use on day 8; Weekly MET; UAs: every weekday | Of 9 Completers:; 55.6% men; Age: 31.2(9.6) | NR | NR | 9 (40.9%) completed study: 5/10 (50%) vs 4/12 (33.3%) | High
Levin, 2013^19^; N=103; 2 Sites (US); 12-week follow-up; DSM IV-TR Cannabis Dependence or ≥12 on the HAM-D.; Comorbid Major Depressive Disorder or Dysthymia | 51 vs 52; 1-week placebo lead-in followed by Venlafaxine 225 mg/day (or MTD); 11 weeks; CM for attendance (transportation; $5-20/visit; 24 visits) and medication adherence ($10/week for returning pill bottles); Weekly CBT/RPT; UA: 2x/week | 73.8% male; Age: approx. 35 years; Race: 45.6% White, 21.3% AA/Black, 26.2% Hispanic, 2.9% Asian, 3.9% Other; Education: 29.2% < high school, Employment: 59.2% unemployed/less than FT | 6/51 vs 19/52 rates of 2+ weeks abstinence favored PBO (P=0.01) | Higher urine-THC levels in venlafaxine group in 2^nd^ half of treatment (wks 6, 8, & 10); P=0.01 | 64 (62.1%) completed study: 31/51 (60.8%) vs 33/52 (63.5%); No difference between groups (P=0.36) | Low
McRae-Clark, 2016^18^; N=76; Single site (US); 8 weeks; DSM IV Cannabis Dependence | 41 vs 35; Vilazodone max dose of 40 mg; CM for attendance ($5/week increasing by $5 each consecutive week + bonuses in weeks 1 [$20] and 12 [$40]) and medication adherence ($10/week for returning pill bottles); 3 sessions MET | 79.0% male; Age: 22.2 (21.3 – 23.1); Race: 54.8%; Caucasian; Education: 94.7% high school graduate | NR | No difference in unadjusted odds (OR=1.22; 95% CI=0.24 to 6.37) or adjusted odds (OR=2.65; 95% CI=0.50 to 14.0) of weekly abstinence | 31 (40.1%) completed study: 14/41 (34.2%) vs 17/35 (48.6%) | Low
Antipsychotics (Atypical): Clozapine, Ziprasidone
Schnell, 2014^24^; N=30; Single site (Germany); Inpatient; 12-month follow-up; DSM-IV Cannabis Abuse or Dependence; Comorbid psychotic spectrum disorder | 16 vs 14; Ziprasidone (M = 200 mg [range 80-400]); Clozapine (M = 225 mg (range 50–425]); 12 months; Outpatient:; Clinical management with psychoED group CBT, and social and occupational rehab.; UA: Inpatient – daily, Outpatient – at 3, 6, 9, 12 mos | 86.7% male; Age: 29 years (8.1); Race: NR; 3% homeless; Education: 90% high school or less; Employment: 83.3% Unemployed | NR | Both groups reduced frequency of cannabis use during follow-up (F=7.15; P=0.023).; No differences between groups (F=2.75; P=0.128). | 12 (40%) completed study:; Ziprasidone: 7/16 (43.8%); Clozapine: 5/14 (35.7%) | High
Anxiolytic: Buspirone
McRae-Clark, 2009^26^; Single site (US); N=93; 12 weeks; DSM IV Cannabis Dependence | 49 vs 44; Buspirone max dose of 60 mg (mean=46 ± 14); CM for attendance ($10 per visit); 3 sessions of MET UA:2x/week at beginning of study, but reduced to 1x/week to improve adherence | 88% male; Age: 31.4 (9.8); Race: 86%; Caucasian | NR | No difference in rate of % negative UA (20.3% vs 6.5%, P=0.13).; No difference on self-reported days of use, | 24 (25.8%) completed study: 11/49 (22.5%) vs 13/44 (29.6%) | Unclear
McRae-Clark, 2015^25^; Single site (US); N=175; 12 weeks; DSM IV Cannabis Dependence | 88 vs 87; Buspirone max dose of 60 mg (mean=42 ± 18); CM for attendance ($5/wk increasing by $5 each consecutive wk + bonuses at in wks 1 [$20] and 12 [$40]) and medication adherence ($10/wk for returning pill bottles); 3 sessions MET | 76.6% male; Age: 24.0 (23.1 – 25.0); Race: 64.0%; Caucasian; Education: 90.3% high school graduate | NR | No difference in unadjusted odds (OR=1.09; 95% CI = 0.45 to 2.61) or adjusted odds (OR=0.75; 95% CI = 0.29 to 1.92) of weekly abstinence | 92 (52.6%) completed study: 45/88 (51.1%) vs 47/87 (54.0%) | Low
Mood Stabilizer: Divalproex Sodium, Lithium Carbonate
Levin, 2004^28^; N=23; Single site (US); 12-week follow-up; DSM IV Cannabis Dependence | 13 vs 12; Divalproex Sodium 1500mg/day (250mg-2000mg depending on response).; 6 weeks; Weekly individual relapse prevention therapy; UA: 2x/week | 99% male; Age: 32; Race: 56% White, 24% AA/Black, 20%; Hispanic; Education: 2 yrs college | 5/13 vs 4/12; No difference in 2+ week abstinence by group or in the length of abstinence. | No difference in % UA(-)s or quantitative THC level. | 10/13 (76.9%) vs 9/12 (75%) for first 6 weeks; 4/9 (44.4%) vs 5/10 (50%) for second 6 weeks (crossover); Study total: 5/13 (38.5%) vs 4/12 (33.3%); No difference in treatment retention. | High
Johnson, 2014^27^; N=31; Single site (Australia); Inpatient (7-day withdrawal); Dec 2010 – Aug 2012; 90 days follow-up; DSM IV-TR Cannabis Abuse or Dependence | 19 vs 22; Lithium 100mg/day; 7 days; Also available:; Paracetamol, Nitrazepam, nicotine treatment.; RPT, relaxation, withdrawal counseling, individual and group psychoED; Inpatient: daily; Outpatient: UA at 14, 30, 90 days. | 65.8 % male; Age: 40.51(12.49); Race: % White NR, 5.3% Indigenous; Education: 86.8%≥10^th^ grade | 3/19 vs 5/22 (90 day); Post-withdrawal 30-day continuous abstinence (no longer on lithium; after 7 day inpatient, assessed at 14, 30, 90 days): No difference | Both groups reduced mean # days of use in the past week (F=7.63, P<0.0001) and mean quantity of daily use (F=7.62, P<0.0001). No difference between groups. | Study completion: 13/19 vs 13/22; 7-day inpatient stay: No difference in retention (P=0.75) | Low
Cognitive-Enhancing: Atomoxetine
McRae-Clark, 2010^29^; N=78; Single site (US); Nov 2005 – Jun 2008; 12-week follow-up; DSM IV Cannabis Dependence; Comorbid ADHD | 39 vs 39; Atomoxetine 100mg/day (or MTD) 4 wks; CM for attendance (nominal); 3 MET sessions in weeks 1-4; UA: 1x week | 80% male; Age: 29.9(10.9); Race: 91% White | NR | No difference in week 12 mean selfreported use, UA results, or % of days used by group. | 16 (20.5%) completed study: 9/39 (23.1%) vs 7/39 (17.9%) | Unclear
CANNABINOIDS: Dronabinol, Nabilone, Nabiximols
Levin, 2011^30^; N=156; Single-site (US); Outpatient; 12-week; DSM IV-TR Cannabis Dependence | 79 vs 77; 1-week placebo lead-in, DRO, 40mg/day 8-weeks + 2-wk taper; CM for attendance and transportation ($5-20 depending on distance + $1.50/visit increasing by $1.50 each consecutive visit and medication adherence ($10/consecutive pair of visits for returning pill bottles); 24 visits up to $570 + transportation; MET + RPT weekly; UA: 2x/week | Sex: 82% male; Age: 37.6 years; Race: 48% White; Education: 27.6% high school or less | No difference in proportion achieving 2 wks abstinence at end of maintenance phase (17.7% vs 15.6%) | Both groups showed reduction in use over time. No differences between groups. | 99 (63.5%) completed study: 55/79 (69.6%) vs 44/77 (57.1%); DRO group had significantly higher retention at end of maintenance phase 77% vs 61% (P=.02) | Low
Levin, 2016^31^; N=122; Single-site (US); Outpatient; 11 weeks; DSM IV Cannabis Dependence | 61 vs 61; Lofex–DRO “fixed-flexible” dose schedule, dose titrated to 1.8 and 60 mg/day or MTD; 11 weeks; CM attendance and transportation ($5-20 depending on distance); MET + RPT weekly; UA: 1x/wk | Sex: 68.9% male; Age: 35.1 (11.0); Race: 38.5% White; Education: 30.3% high school or less | Proportion achieving abstinence in last 2 wks of trial: 12/61 (19.67%) vs 12/61 (19.67%). No difference in 2 consecutive wks abstinence (X_12_=.02, P=.89); Proportion achieving abstinence during any 21 days: 17/61 (27.87%) vs 18/61 (29.51%). No difference in achieving 21 days consecutive abstinence (X_12_=.17, P=.68). | NR | 79 (64.8%) completed study: 37/61 (60.66%) vs 42/61 (68.85%).; No difference between groups (X_12_=1.36, P=.24) | Unclear
Hill, 2017^32^; N=18; Single site (US); 14 weeks; DSM IV Cannabis Dependence | 10 vs 8; Nabilone 2mg/day for 10 wks.; CM for attendance ($40 bonus for all 4 visits) and completed diaries ($100 each) up to $955.; MM weekly; UA: Outpatient 2x/wk for 10-week study; Follow-up UA at 14 wks | Sex: 67% male; Age: 26.4 (6.5) years; Race: 67% White; Education: 14.4 (3.4) years | NR | No difference in cannabis use sessions (P=0.53).; No difference in the % days of use at the end of treatment (P=0.22) or follow-up (P=0.81).; No difference in the urine cannabinoid levels at the end of treatment (P=0.17) or follow-up (P=0.34). | 12 (66.7%) completed study: 6/10 (60%) vs 6/8 (75%) | Unclear
Trigo, 2018^33^; N=40; Single site (Canada); Outpatient; 12 weeks; DSM IV Cannabis Dependence | 20 vs 20; Nabiximols (113.4 mg THC/105 mg CBD): self-titrated up to 42 sprays/day 12 weeks; CM for attendance and transportation (C$6 visit + random non-monetary prize or C$5-50 gift card, up to C$855; 24 visits); CBT/MET; UA: 2x week | 72.5% male; Age: 33.0 (11.75); Race: 60% White; Education: 62.5% completed college; Employment: 12.5% FT | NR | 7-day point prevalence abstinence after medication phase 30.8% (N=4) vs 42.9% (N=6); Use declined for both groups, but no difference between groups (P=.179) | 13/20 (65%) vs 14/20 (70%) | Unclear
Allsop, 2014^34^; N=51; 2 sites (Australia); Inpatient (9 days); 28-day follow-up; DSM IV-TR Cannabis Dependence | 27 vs 24; Nabiximols, maximum dose 86.4 mg THC, 80 mg CBD; 3 days washout; 6 days medication; Self-completed CBT workbook; CM for attending follow up visit AU$40; UA: Inpatient – 3x during 9-day phase.; Outpatient – 1x at 28-day follow-up | 76% male; Age: 35.39; Race: % White NR;; 6% Aboriginal/Native; Education: 55% completed school; Employment: 53% Unemployed | NR | No difference in use between groups from baseline to follow-up (P=0.29) | 19 (37.3%) completed study: 11/27 (40.7%) vs 8/24 (33.3%); T group remained in treatment longer during medication phase (unadjusted HR=3.66 [95%CI=1.18 to11.37]; P=.02) | Low
ANTICONVULSANTS: Gabapentin, Topiramate
Mason, 2012^36^; N=50; Single-site (US); 13 wks; DSM IV Cannaibis Dependence | 25 vs 25; Gabapentin; 1200 mg/day; 12 wks; Weekly manual-guided (MET & CBT) individual counseling | 80% Male; Age: 33.9 (9.7); Race: 76% White; Education years: 14 (1.9) | NR | More UA(-) with GAB (P=0.001), greater decrease of self-reported use days/week (P=0.004) | 32 (64%) completed study: 18/25 (72%) vs 14/25 (56%) | Unclear
Miranda, 2017^35^; N=66; Single-site (US); 7 wks; DSM IV Cannabis Dependence | 40 vs 26; Topiramate 200mg/day; 6 wks; 3-session manual-driven MET | Youth 15-24; 48% Male; Age: 19.5; Race: 52% White | NR | No difference in UA(-) (P=0.335) or change in UA results between weeks 1-6 (P=0.746) | 39 (59.1%) completed study: 19/40 (52.5%) vs 20/26 (23.1%); Significant T effect (P=0.018) | Unclear
OTHER PHARAMACOTHERAPIES
Mucolytic: N-acetylcysteine
Gray, 2012^38^; N=116; Single-site (US); 12 wks; No diagnosis necessary – self-reported regular cannabis users. | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | NS trend favoring NAC for end-of-treatment (2-week) abstinence: OR=2.32 (95% CI: 0.99 to 5.43); P=0.054; No difference in 4 wk end-of-treatment abstinence: OR=2.14 (95% CI: 0.85 to 5.42); P=0.108 | More weekly UA(-) with NAC: 40.9% vs 27.2%, OR=2.35 (95% CI: 1.05 to 5.24); P=0.029; Posttreatment follow-up UA(-): 19% vs 10.3%; OR=2.4 (95% CI: 0.8 to 7.5); P=0.131 | 70 (60.3%) completed study: 37/58 (64%) vs 33/58 (57%); 54 (46.6%) completed 4-wk follow-up: 29 (50%) vs 25 (43%) | Low
Gray, 2017^37^; N=302; 6 sites (US); 16 wks; DSM IV-TR Cannabis Dependence | 153 vs 149; NAC 2400mg/day; 12 wks; CM for attendance ($10 for first visit increasing by $2 each consecutive visit, maximum of $30/visit 24 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA- , maximum of $25/visit; 36 visits); MM 1x/wk; UA 3x week | 72% male; Age: 30.3 (9.03); Race: 58.3% White, 27.8% AA/Black; Education: 31.2%≤ high school; Employment: 30.1% unemployed | NR | No difference between weekly UA(-): 22.3% vs 22.4%; OR=1.00 (95% CI: 0.63– 1.59), P=0.984 | 216 (71.5%) completed study: 113/153 (71.9%) vs 103/149 (68.5%) | Low
Antiemetic/Antinauseant: Aprepitant
The Scripps Research Institute^39^; Unpublished; N=20; single-site (US); 2014-2016; 12 wks; DSM IV Cannabis Dependence | 10 vs 10; Aprepitant 125mg/d; 8 wks; Manual-guided behavioral counseling | 85% male; Age: 35.0 (SD=11.3); Other; demographics: NR | NR | Change in use from Week 0 to 8 using Urinary CN-THCCOOH Levels [Units: ng/mg]: 198.3 (SD=389.4) vs 55.9 (SD=239.3); No statistical analysis provided | 16 (80%) completed study: 6/10 (60%) vs 10/10 (100%) | Unclear
Hormone: Oxytocin
Sherman, 2017 ^40^; N = 16; Site(s) not reported; 4-month follow-up; DSM IV Cannabis Dependence | 8 vs 8; Oxytocin (40 IU) administered intranasally prior to MET sessions; 4 wks; MET | 62.5% male; Age: 25.5 (7.6); Race: 56.3% White; Education: 62.5% some college or more | NR | NS group by time interaction for mean daily cannabis use (P=0.785). | NR | High

* Descriptors may represent the total study population or the subgroup assigned to active treatment unless a significant difference occurred between study arms at baseline.

Other benefits/harms Not Reported in these studies.

** As reported.

Abbreviations: AA = African American; ADHD = Attention Deficit Hyperactivity Disorder; AE = adverse event; AU = Australian; BAI = Beck Anxiety Inventory; C = control group; Can = Canadian; CBD = cannabidiol; CBT = cognitive behavioral therapy; CI = Confidence interval; CM = contingency management; CN-THCCOOH = creatinine normalized 11-nor-9-carboxy-_Δ9_-tetrahydrocannnabinol; DRO = Dronabinol; DSM = Diagnostic and Statistical Manual of Mental Disorders; FT = full-time; GAB = gabapentin; HAM-D = Hamilton Depression Rating Scale; IU = international unit; MD = mean difference; MET= Motivational Enhancement Therapy; mg = milligrams; MM = medication management; MTD = maximum tolerated dose; MWC= Marijuana Withdrawal Checklist; NAC = N-acetylcysteine; ng = nanogram; NR = Not reported; NS = not significant; OR = Odds ratio; P = p-value; PBO = placebo; PRN = as needed;-ROB = risk of bias; RPT= Relapse Prevention Therapy; SAE = serious adverse event; SD = standard deviation; SEM = standard error of the mean; SERT = sertraline; SES = socioeconomic status; sig = statistically significant; SMD = standard mean difference; SNRI = serotonin and norepinephrine reuptake inhibitor; SSRI = selective serotonin reuptake inhibitor; T = treatment group; THC = Tetrahydrocannabinol; UA = urinalysis; US = United States; wk(s) = week(s); yrs = years.

Table 3 Trials of psychopharmacotherapies for treating secondary outcomes of cannabis use disorder

Setting; N Randomized; # of Sites; Mean follow-up | N, T vs C; Treatment dose & duration; Concomitant treatment; UA frequency | Population^*^; Male %; Age, mean (SD); Race %; SES | Treatment vs Comparator | | | Risk of bias
Setting; N Randomized; # of Sites; Mean follow-up | N, T vs C; Treatment dose & duration; Concomitant treatment; UA frequency | Population^*^; Male %; Age, mean (SD); Race %; SES | Treatment dropouts due to AE; Serious AEs | Cannabis withdrawal symptoms | Other Outcomes | Risk of bias
PSYCHOPHARMACOTHERAPIES
Selective Serotonin Reuptake Inhibitors (SSRIs): Escitalopram, Fluoxetine
Weinstein, 2014^22^; N=52; Single site (Israel); 23-week follow-up; DSM IV Cannabis Dependence; Comorbid Major Depressive Disorder | 26 vs 26; Escitalopram 10 mg; 9 wks; 60 min group CBT 1x/wk + MET.; Instructed to stop cannabis use after 4 weeks.; UA: every 2 wks after wk 4 | 75% male; Age: 32.71 (6.8); Race: NR; Education: 12.42 (2) | No difference in dropouts due to AEs. | Withdrawal symptoms reduced in both groups, but no difference between groups. | No difference in medication adherence. Higher treatment compliance with placebo (P=0.016). No difference in depression or anxiety reduction. | High
Cornelius, 2010^20^; N=70; Single site (US); 12-week follow-up; DSM IV CUD^**^ or HAM-D ‡ 15; Comorbid Major Depressive Disorder | 34 vs 36; Fluoxetine 10mg first 2 weeks/ 20mg wks 3-12; 12 wks; CBT (9 therapy sessions over 12 wks) + MET; CM: $20 for each assessment visit; UA: frequency unspecified | 61.4% male; Age: 21 (2.4); Race: 55.7%; White, 37.1; AA/Black, 7.1%; Mixed; SES: NR | No dropouts due to AEs or SAEs | NR | Clinically (but not significant) improvement in depressive symptoms in both groups. No difference between groups. | Low
Other Antidepressants: Bupropion, Nefazodone, Venlafaxine, Vilazodone
Carpenter, 2009^21^; N=106; 2 Sites (US); 13-week follow-up; DSM IV Cannabis Dependence | 40 vs 36 vs 30; Bupropion 300 mg/day vs Nefazodone 600 mg/day (or MTD) vs PBO; CM for attendance ($5/visit; 26 visits) Individual coping skills-based CBT; UA: 2x/week | 76.4% male; Age: 32(10) years; Race: 34% White, 27% AA/Black, 28% Hispanic; Education: 42.5% high school or less; Employment: 9.4% Unemployed | Dropouts: 1 vs 0 vs 0; no difference; 5 vs 9 vs 1 moderate or serious AEs – no difference | No difference on difficulty falling asleep, sleep disturbances, irritability, or anxiety. | No difference in effect on cannabis dependency severity (P=0.14). Clinical improvement over course of study for all groups, but no difference between groups.; More missed doses with nefazodone vs placebo (P=0.019). No difference from bupropion. | Low
Penetar, 2012^23^; N=22; Single site (US); 4-week follow-up; DSM-IV Cannabis Abuse or Dependence. | 10 vs 12; 7-day baseline period.; Bupropion 300mg/day; Instructed to stop cannabis use on day 8 Weekly MET; UAs: every weekday | Of 9 Completers:; 55.6% men; Age: 31.2(9.6) | NR | No difference in withdrawal symptoms. Cannabis withdrawal scores increased for PBO but not BUP. Significantly lower craving for T vs C. No difference in depression, anxiety, or readiness to change. No difference in hours slept, latency to sleep, or ratings of sleep. | No difference on cognitive tests. | High
Levin, 2013^19^; N=103; 2 Sites (US); 12-week follow-up; DSM IV-TR Cannabis Dependence or ‡12 on the HAM-D.; Comorbid Major Depressive Disorder or Dysthymia | 51 vs 52; 1-week placebo lead-in followed by; Venlafaxine 225 mg/day (or MTD); 11 weeks; CM for attendance (transportation; $5-20/visit; 24 visits) and medication adherence ($10/week for returning pill bottles); Weekly CBT/RPT; UA: 2x/week | 73.8% male; Age: approx. 35 years; Race: 45.6%; White, 21.3%; AA/Black, 26.2%; Hispanic, 2.9%; Asian, 3.9% Other; Education: 29.2% < high school, Employment: 59.2% unemployed/less than FT | NR | NR | Depressive symptoms improved for both groups, with no difference between groups. No differences in medication or behavioral therapy compliance. | Low
McRae-Clark, 2016^18^; N=76; Single site (US); 8 weeks; DSM IV Cannabis Dependence | 41 vs 35; Vilazodone max dose of 40 mg; CM for attendance ($5/week increasing by $5 each consecutive week + bonuses in weeks 1 [$20] and 12 [$40]) and medication adherence ($10/week for returning pill bottles); 3 sessions MET | 79.0% male; Age: 22.2 (21.3 – 23.1); Race: 54.8%; Caucasian; Education: 94.7% high school graduate | Dropouts: 2/41 vs 1/35; SAEs: 0/41 vs 1/35 (not considered study related) | | One subscale of cannabis craving (purposefulness) decreased more for the vilazodone group (F=6.7,P=0.012). No differences on other subscales of cannabis craving. | Low
Schnell, 2014^24^; N=30; Single site (Germany); Inpatient; 12-month follow-up; DSM-IV Cannabis Abuse or Dependence; Comorbid psychotic spectrum disorder | 16 vs 14; Ziprasidone (M = 200 mg [range 80-400]); Clozapine (M = 225 mg (range 50–425]); 12 months; Outpatient: Clinical management with psychoED, group CBT, and social and occupational rehab.; UA: Inpatient - daily, Outpatient – at 3, 6, 9, 12 mos | 86.7% male; Age: 29 years (8.1); Race: NR; 3% homeless; Education: 90% high school or less; Employment: 83.3% Unemployed | Clozapine was associated with more side effects (F=8.2; P=0.017) | NR | Positive symptoms decreased in both groups, with a stronger decline with clozapine (P=0.05). Ziprasidone was associated with more emergency sessions (P=0.022), higher group therapy attendance (P=0.024), and higher drug attitude inventory score (P=0.005). | High
Anxiolytic: Buspirone
McRae-Clark, 2009^26^; Single site (US); N=93; 12 weeks; DSM IV Cannabis Dependence | 49 vs 44; Buspirone max dose of 60 mg (mean=46 ± 14); CM for attendance ($10 per visit); 3 sessions of MET; UA:2x/week at beginning of study, but reduced to 1x/week to improve adherence | 88% male; Age: 31.4 (9.8); Race: 86%; Caucasian | Dropous: 1/49 vs 1/44; Serious AEs: none | NR | Trend toward faster time to first UA(-) in T group (P=0.098). No difference on anxiety, or measures of craving. | Unclear
McRae-Clark, 2015^25^; Single site (US); N=175; 12 weeks; DSM IV Cannabis Dependence | 88 vs 87; Buspirone max dose of 60 mg (mean=42 ± 18); CM for attendance ($5/wk increasing by $5 each consecutive wk + bonuses at in wks 1 [$20] and 12 [$40]) and medication adherence ($10/wk for returning pill bottles); 3 sessions MET | 76.6% male; Age: 24.0 (23.1 – 25.0); Race: 64.0%; Caucasian; Education: 90.3% high school graduate | Dropouts: 2/88 vs 4/87; Serious AEs: 2/88 vs 1/87 (none were considered study-related) | NR | Cannabis craving decreased during treatment, but no difference between groups (F=1.64, P=0.20). | Low
Mood Stabilizer: Divalproex Sodium, Lithium Carbonate
Levin, 2004^28^; N=23; Single site (US); 12-week follow-up; DSM IV Cannabis Dependence | 13 vs 12; Divalproex Sodium 1500mg/day (250mg-2000mg depending on response).; 6 weeks; Weekly individual relapse prevention therapy; UA: 2x/week | 99% male; Age: 32; Race: 56% White, 24% AA/Black, 20% Hispanic; Education: 2 yrs college | Dropouts: 3/13 vs 1/12; SAEs: NR | No differences in craving or irritability. | Suggestion of poor medication compliance associated in divalproex (no statistical analysis reported). | High
Johnson, 2014^27^; N=31; Single site (Australia); Inpatient (7-day withdrawal); Dec 2010 – Aug 2012; 90 days follow-up; DSM IV-TR Cannabis Abuse or Dependence | 19 vs 22; Lithium 100mg/day; 7 days; Also available: Paracetamol, Nitrazepam, nicotine treatment.; RPT, relaxation, withdrawal counseling, individual and group psychoED; Inpatient: daily; Outpatient: UA at 14, 30, 90 days. | 65.8 % male; Age: 40.51(12.49); Race: % White; NR, 5.3%; Indigenous; Education: 86.8%≥10^th^ grade | None | Withdrawal severity: no difference between groups.; T was more effective than C for attenuating nightmares/strange dreams for withdrawal period (P=0.005), as well as for loss of appetite (P=0.001), and stomach aches (P=0.05). Trend towards reducing withdrawal-related physical tension (P=0.06). | QOI: Physical, but not psychological, health or social relations improved in T group (P<0.05).; No differences in severity of dependence or cannabis problems | Low
Cognitive-Enhancing: Atomoxetine
McRae-Clark, 2010^29^; N=78; Single site (US); Nov 2005 – Jun 2008; 12-week follow-up; DSM IV Cannabis Dependence; Comorbid ADHD | 39 vs 39; Atomoxetine 100mg/day (or MTD); 4 wks; CM for attendance (nominal); 3 MET sessions in weeks 1-4; UA: 1x week | 80% male; Age: 29.9(10.9); Race: 91% White | Dropouts: No difference (1 vs 1) | NR | Greater improvement on CGI with T (P=0.02); No difference in change in ADHD severity ratings.; T had a greater rate of ADHD symptom decline than C in weeks 1-4 (P=0.023), but there was no subsequent difference between groups.; No difference in heavy use days by group. | Unclear
CANNABINOIDS: Dronabinol, Nabilone, Nabiximols
Levin, 2011^30^; N=156; Single-site (US); Outpatient; 12-week; DSM IV-TR Cannabis Dependence | 79 vs 77; 1-week placebo lead-in, DRO, 40mg/day 8-weeks + 2-wk taper; CM for attendance and transportation ($5-20 depending on distance + $1.50/visit increasing by $1.50 each consecutive visit and medication adherence ($10/consecutive pair of visits for returning pill bottles); 24 visits up to $570 + transportation; MET + RPT weekly; UA: 2x/week | Sex: 82% male; Age: 37.6 years; Race: 48% White; Education: 27.6% high school or less | SAEs: 3 vs 1 | Significantly greater drop in withdrawal symptoms over time in T vs C (P=.02) | NR | Low
Levin, 2016^31^; N=122; Single-site (US); Outpatient; 11 weeks; DSM IV Cannabis Dependence | 61 vs 61; Lofex–DRO “fixed-flexible” dose schedule, dose titrated to 1.8 and 60 mg/day or MTD 11-weeks; CM attendance and transportation ($5-20 depending on distance); MET + RPT weekly; UA: 1x/wk | Sex: 68.9% male; Age: 35.1 (11.0); Race: 38.5% White; Education: 30.3% high school or less | SAEs: 1 vs 1 | Main effects model: No effect of T on withdrawal scores across time (F_1,633_=.05, P=.83) | NR | Unclear
Hill, 2017^32^; N=18; Single site (US); 14 weeks; DSM IV Cannabis Dependence | 10 vs. 8; Treatment: 2mg/day of Nabilone; Placebo for the 10-week duration CM for attendance ($40 bonus for all 4 visits) and completed diaries ($100 each) up to $955.; MM weekly; UA: Outpatient 2x weekly for the duration of the 10-week study; Follow-up UA at 14 wk. | Sex: 67% male; Age: 26.4 (6.5) years; Race: 67% White; Education: 14.4 (3.4) years | NR | No differences at end of treatment (Z=0.34, P= 0.74) or end of follow-up (Z=0.40, P=0.69) | Craving: no difference at end of treatment (P=0.74), or end of follow-up (P=0.69); Anxiety: No difference at end of treatment (P=0.50), or end of follow-up (P=0.92) | Unclear
Trigo, 2018^33^; N=40; Single site (Canada); Outpatient; 12 weeks; DSM IV Cannabis Dependence | 20 vs 20; Nabiximols (113.4 mg THC/105 mg CBD): self-titrated up to 42 sprays/day; 12 weeks; CM for attendance and transportation (C$6 visit + random non-monetary prize or $5-50 gift card, up to C$855; 24 visits); CBT/MET; UA: 2x week | 72.5% male; Age: 33.0 (11.75); Race: 60% White; Education: 62.5% completed college; Employment: 12.5% FT | NR | Withdrawal symptoms decreased for both, but no difference between groups over time (P=.601) | Lower craving with T vs C (P<.05) | Unclear
Allsop, 2014^34^; N=51; 2 sites (Australia); Inpatient (9 days); 28-day follow-up; DSM IV-TR Cannabis Dependence | 27 vs 24; Nabiximols, maximum dose 86.4 mg THC, 80 mg CBD; 3 days washout; 6 days medication; Self-completed CBT workbook; CM for attending follow up visit AU$40; UA: Inpatient– 3x during 9-day phase.; Outpatient 1x at 28-day follow-up | 76% male; Age: 35.39; Race: % White; NR; 6%; Aboriginal/Native; Education: 55% completed school; Employment: 53% Unemployed | Dropout: 0 vs 0; SAEs; 0 vs 1, No difference (P=.10) | Over the duration of the study:; T reduced overall severity of cannabis withdrawal vs C (P=.01); Reduction of cravings: Favored T (P=.03); Lower irritability, anger, and aggression: Favored T (P=.004); Reduction in depressive symptoms: Favored T (P=.05); Shorter course of withdrawal: Favored T (P=.04); NS positive benefit on sleep disturbance, anxiety, appetite loss, physical symptoms, and restlessness. | NR | Low
ANTICONVULSANTS: Gabapentin, Topiramate
Mason, 2012^36^; N=50; Single-site (US); 13 wks; DSM IV Cannaibis Dependence | 25 vs 25; Gabapentin 1200 mg/day; 12 wks; Weekly manual-guided (MET & CBT) individual counseling | 80% Male; Age: 33.9 (9.7); Race: 76% White; Education years: 14 (1.9) | Dropouts: 1 vs 1; Serious AE: None | Greater improvement in withdrawal symptoms with GAB (P<0.001); Sleep: Better sleep quality, duration, and efficiency, and lower sleep medication use, sleep disturbance, and daytime dysfunction with GAB (all P<0.001) | Depressive symptoms: Greater improvement with T (P=0.009); Craving: Greater reduction with T (P<0.001); Cannabis-related consequences: Greater reductions with T (P=0.02); Cannabis related problems: Greater improvement with T on psychological (P=0.028) and physical (P=0.046).; Neurocognitive performance: Greater improvement with T (P=0.029).; Medication compliance: No difference | Unclear
Miranda, 2017^35^; N=66; Single-site (US); 7 wks; DSM IV Cannabis Dependence | 40 vs 26; Topiramate 200mg/day; 6 wks; 3-session manual-driven MET | Youth 15-24; 48% Male; Age: 19.5; Race: 52% White | Dropouts: 14 vs 1; Serious AE: NR | NR | Depressive symptoms: No difference in overall scores, greater reduction in symptoms with PBO (P=0.022).; Neurocognitive performance: Decreased retrieval performance and memory with T; Medication compliance: No difference | Unclear
OTHER PHARAMACOTHERAPIES
Mucolytic: N-acetylcysteine
Gray, 2012^38^; N=116; Single-site (US); 12 wks; No diagnosis necessary – self-reported regular cannabis users. | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | Dropouts: 1 vs 0; Serious AEs: None | NR | Adherence (% of dispensed doses taken): 95% vs 93% | Low
Gray, 2017^37^; N=302; 6 sites (US); 16 wks; DSM IV-TR Cannabis Dependence | 153 vs 149; NAC 2400mg/day; 12 wks; CM for attendance ($10 for first visit increasing by $2 each consecutive visit, maximum of $30/visit 24 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA- , maximum of $25/visit; 36 visits); MM 1x/wk; UA 3x week | 72% male; Age: 30.3 (9.03); Race: 58.3%; White, 27.8%; AA/Black; Education: 31.2%≤ high school; Employment: 30.1% unemployed | Dropouts: 0; Serious AEs: 1 vs 6 | NR | Adherence (UA confirmed N taking ≥80% of medication/week): 31 vs 26; Adherence (self-report + pill count) N taking ≥80% of medication/ wk: 87 vs 78 | Low
Antiemetic/Antinauseant: Aprepitant
The Scripps Research Institute^39^; Unpublished; N=20; single-site (US); 2014-2016; 12 wks; DSM IV Cannabis Dependence | 10 vs 10; Aprepitant 125mg/d; 8 wks manual-guided behavioral counseling; 8 wks | 85% male; Age: 35.0; (SD=11.3); Other; demographics: NR | NR | NR | NR | Unclear
Hormone: Oxytocin
Sherman, 2017 ^40^; N = 16; Site(s) not reported; 4-month follow-up; DSM IV Cannabis Dependence | 8 vs 8; Oxytocin (40 IU) administered intranasally; 4 wks; MET for 4 wks | 62.5% male; Age: 25.5 (7.6); Race: 56.3% White; Education: 62.5% some college or more | None | NR | NR | High

* Descriptors may represent the total study population or the subgroup assigned to active treatment unless a significant difference occurred between study arms at baseline.

Other benefits/harms Not Reported in these studies.

** As reported.

Abbreviations: AA = African American; ADHD = Attention Deficit Hyperactivity Disorder; AE = adverse event; AU = Australian; BAI = Beck Anxiety Inventory; C = control group; Can = Canadian; CBD = cannabidiol; CBT = cognitive behavioral therapy; CI = Confidence interval; CM = contingency management; CN-THCCOOH = creatinine normalized 11-nor-9-carboxy-_Δ9_-tetrahydrocannnabinol; DRO = Dronabinol; DSM = Diagnostic and Statistical Manual of Mental Disorders; FT = full-time; GAB = gabapentin; HAM-D = Hamilton Depression Rating Scale; IU = international unit; MD = mean difference; MET= Motivational Enhancement Therapy; mg = milligrams; MM = medication management; MTD = maximum tolerated dose; MWC= Marijuana Withdrawal Checklist; NAC = N-acetylcysteine; ng = nanogram; NR = Not reported; NS = not significant; OR = Odds ratio; P = p-value; PBO = placebo; PRN = as needed;-ROB = risk of bias; RPT= Relapse Prevention Therapy; SAE = serious adverse event; SD = standard deviation; SEM = standard error of the mean; SERT = sertraline; SES = socioeconomic status; sig = statistically significant; SMD = standard mean difference; SNRI = serotonin and norepinephrine reuptake inhibitor; SSRI = selective serotonin reuptake inhibitor; T = treatment group; THC = Tetrahydrocannabinol; UA = urinalysis; US = United States; wk(s) = week(s); yrs = years.

## KEY QUESTION 2 Are there known subpopulations for whom currently used pharmacotherapy is most/least effective for cannabis use disorder?

We identified 7 RCTs exploring the differential effects of pharmacotherapy for subjects with cannabis use disorder by subpopulation. Overall, findings are insufficient due to the limited number of studies examining each subpopulation/outcome.

### Demographic Subpopulations: Gender, Race, Age

Four RCTs examined subgroup differences by gender.^18,20,37,38^ Findings suggest no gender differences in abstinence or time to dropout associated with N-acetylcysteine,^37,38^ that vilazodone may be less effective than placebo for the reduction of cannabis use in females but not males,^18^ and that females may experience greater benefit from fluoxetine than males (ie, cannabis dependence criteria and depressive symptoms).^20^ Two trials of N-acetylcysteine explored racial and ethnic differences and differences by age. Findings from 1 trial suggest that regardless of group assignment, non-White and Hispanic subjects may have lower proportions of negative UAs.^37^ The second trial reported no differences in time to dropout by race.^38^ For comparisons by age, in a trial of N-acetylcysteine in adults, when limiting abstinence results to subjects aged 18-21 (N=58), rates of achieving abstinence were 2 times higher with N-acetylcysteine versus placebo; however, the difference was not statistically significant.^37^ The other trial, of adolescents and young adults, found no difference in time to dropout by age (see Table 4 for more detail).^38^

### Other Subpopulations: Baseline Cannabis Use, Baseline Tobacco Use, Comorbid ADHD and other Mental Health Conditions

Three RCTs examined differences in effect by baseline cannabis use.^21,29,38^ Findings indicate that baseline use was a stronger predictor of end-of-study use than randomization to atomoxetine or placebo.^29^ Among subjects with severe cannabis dependence at baseline, there was no difference between nefazodone or bupropion over placebo for end-of-study severity reduction.^21^ No difference by baseline cannabis use or severity was observed when comparing N-acetylcysteine to placebo.^38^ Two RCTs of N-acetylcysteine compared effects by baseline tobacco use and found higher rates of abstinence among non-tobacco users, and no effect on time to dropout.^37,38^ Three RCTs examined subgroup differences related to mental health conditions. Among subjects with both ADHD and cannabis use disorder randomized to atomoxetine or placebo, results indicate no significant difference in cannabis use reduction or ADHD symptoms by baseline ADHD severity.^29^ In addition, a trial comparing N-acetylcysteine to placebo found no difference in time to dropout by ADHD or any other comorbid mental health condition.^38^ Finally, 1 RCT of venlafaxine in subjects with major depressive disorder examined the relationship between improvement in depressive symptoms and urine THC levels. Results indicated that for subjects randomized to placebo, THC levels went down as depressive symptoms decreased. For those randomized to venlafaxine, THC levels remained high despite mood improvements (see Table 4 for more detail).^19^

Table 4 Subgroup analyses in studies of pharmacotherapy for cannabis use disorder, stratified by population characteristic

Study | N, T vs C Dose and duration Concomitant Tx UA frequency | Population*; Male %; Age, mean (SD); Race %; SES | Outcome: Findings | Summary of findings
DEMOGRAPHICS
Gender
Cornelius, 2010^20^; N=70; Single site (US); 12-week follow-up; Comorbid Major Depressive Disorder | 34 vs 36; Fluoxetine 10mg first 2 weeks/ 20mg wks 3-12; 12 wks; CBT (9 therapy sessions over 12 wks) + MET; UA: frequency unspecified | 61.4% male; Age: 21 (2.4); Race: 55.7% White, 37.1 AA/Black, 7.1% Mixed; SES: NR | No differences in the reduction of cannabis use or end-of-study depressive symptom scores by gender. However, females showed greater improvement in depression symptoms and a greater reduction in cannabis abuse criteria over time. | No differences in the reduction of cannabis use or end-of-study depressive symptom scores by gender. However, females showed greater improvement in depression symptoms and a greater reduction in cannabis abuse criteria over time.
McRae-Clark, 2016^18^; N=76; Single site (US); 8 weeks | 41 vs 35; Vilazodone max dose of 40 mg; CM for attendance ($5/week increasing by $5 each consecutive week + bonuses in weeks 1 [$20] and 12 [$40]) and medication adherence ($10/week for returning pill bottles); 3 sessions MET | 79.0% male; Age: 22.2 (21.3 - 23.1); Race: 54.8%; Caucasian; Education: 94.7% high school graduate | [underlined: Study cannabinoid levels:] Males vs females (Ln[Cannab]=0.99±0.15 vs 1.72±0.28, P=0.25).; Males randomized to vilazodone had lower urinary cannabinoid levels vs placebo (Ln[Cannab]=0.86±0.24 vs 1.16±0.19).; Females randomized to vilazodone had higher urinary cannabinoid levels vs placebo (Ln[Cannab]=1.84±0.31 vs 1.17±0.36).; [underlined: Prevalence of UA-:] Male vs female (5.6% [27-480] vs. 0.8% [1/128], P=0.079). Primary effect of T vs C on use in males = NS.; [underlined: Craving:] A reduction in the Purposefulness subscale of the MCQ in males randomized to vilazodone (7.0±0.7 vs. 10.0±0.6, P < .001) but not in females (12.8± 1.6 vs. 12.0± 1.8, P=0.761).; [underlined: Total MCQ Score:] No difference by gender. | Males randomized to vilazodone had lower cannabinoid levels vs placebo; however, the opposite was true for females.
Gray, 2017^37^; N=302; 6 sites (US); 16 wks | 153 vs 149; NAC 2400mg/day; 12 wks; CM for attendance ($10 for first visit increasing by $2 each consecutive visit, maximum of $30/visit 24 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA- , maximum of $25/visit; 36 visits); MM 1x/wk; UA 3x week | 72% male; Age: 30.3 (9.03); Race: 58.3% White, 27.8% AA/Black; Education: 31.2%≤ high school; Employment: 30.1% unemployed | Gender was not a significant predictor of cannabis abstinence, and there was no sex-by-treatment interaction. | No difference in abstinence by gender.
Gray, 2012^38^; N=116; Single-site (US); 12 wks | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | No difference in time to dropout by gender. | No difference in time to dropout by gender.
Race
Gray, 2017^37^; N=302; 6 sites (US); 16 wks | 153 vs 149; NAC 2400mg/day; 12 wks; CM for attendance ($10 for first visit increasing by $2 each consecutive visit, maximum of $30/visit 24 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA- , maximum of $25/visit; 36 visits); MM 1x/wk; UA 3x week | 72% male; Age: 30.3 (9.03); Race: 58.3% White, 27.8% AA/Black; Education: 31.2%≤ high school; Employment: 30.1% unemployed | Proportion UA-: Lower proportions of UA-s amongst non-White subjects. However, there was a trend towards non-Whites higher rates of UA-s with NAC (vs placebo) than Whites: White (OR=0.81, 95% CI: 0.46-1.44); non-White (OR=1.97, 95% CI: 0.84-4.63), P=0.083.; Hispanics were half as likely as non-Hispanics to test negative for cannabinoids during treatment (OR=0.52, 95% CI: 0.27-1.00, P=0.030), but there was no ethnicity-by-treatment interaction (P=0.881). | Lower proportions of UA-s amongst non-White subjects; Lower rates of UA- among Hispanic subjects vs non-Hispanics regardless of treatment group.
Gray, 2012^38^; N=116; Single-site (US); 12 wks | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | No difference between White and non-White subjects in time to dropout. | No difference between White and non-White subjects in time to dropout.
Age
Gray, 2017^37^; N=302; 6 sites (US); 16 wks | 153 vs 149; NAC 2400mg/day; 12 wks; CM for attendance ($10 for first visit increasing by $2 each consecutive visit, maximum of $30/visit 24 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA- , maximum of $25/visit; 36 visits); MM 1x/wk; UA 3x week | 72% male; Age: 30.3 (9.03); Race: 58.3% White, 27.8% AA/Black; Education: 31.2%≤ high school; Employment: 30.1% unemployed | Age 18-21 (N=58): When the sample was limited to ages 18-21, subjects receiving NAC had twice the rate of achieving abstinence. The difference was not significant (OR=2.03, 95% CI: 0.70-5.86, P=0.187). | Among subjects 18-21 rates of abstinence were 2 times higher with NAC (difference was not significant).
Gray, 2012^38^; N=116; Single-site (US); 12 wks | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | No difference in time to dropout by age (among adolescents and young adults). | No difference in time to dropout by age (among adolescents and young adults).
SUBSTANCE USE
Baseline Cannabis Use or Severity
Carpenter, 2009^21^; N=106; 2 Sites (US); 13-week follow-up | 40 vs 36 vs 30; Bupropion 300 mg/day vs Nefazodone 600 mg/day (or MTD) vs PBO CM for attendance ($5/visit; 26 visits); Individual coping skills-based CBT; UA: 2x/week | 76.4% male; Age: 32(10) years; Race: 34% White, 27%; AA/Black, 28% Hispanic; Education: 42.5% high school or less; Employment: 9.4% Unemployed | No difference in cannabis dependence symptoms at baseline on a reduction in symptom severity in the bupropion and nefazodone groups vs placebo (P=0.07). There was no significant difference in the effect of treatment on severity reduction (P=0.14). | No difference in dependence severity with nefazodone and bupropion vs placebo in subjects with more severe symptoms at baseline.
McRae-Clark, 2010^29^; N=78; Single site (US); Nov 2005 – Jun 2008; 12-week follow-up; Comorbid ADHD | 39 vs 39; Atomoxetine 100mg/day (or MTD); 4 wks; CM for attendance (nominal); 3 MET sessions in weeks 1-4; UA: 1x week | 80% male; Age: 29.9(10.9); Race: 91% White | Higher baseline use was associated with higher week 12 mean self-reported use (βˆ=0.51, SE=0.12; P<0.001), explaining 36% of the residual variation. In contrast, the randomized treatment assigned only explained 1.7% of the residual variance after adjustment for baseline use. | Baseline use was a stronger predictor of end-of-study use than atomoxetine.
Gray, 2012^38^; N=116; Single-site (US); 12 wks | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | No difference in time to dropout by baseline cannabis use or severity. | No difference in time to dropout by baseline cannabis use or severity.
Baseline Tobacco Use
Gray, 2017^37^; N=302; 6 sites (US); 16 wks | 153 vs 149; NAC 2400mg/day; 12 wks; CM for attendance ($10 for first visit increasing by $2 each consecutive visit, maximum of $30/visit 24 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA- , maximum of $25/visit; 36 visits); MM 1x/wk; UA 3x week | 72% male; Age: 30.3 (9.03); Race: 58.3% White, 27.8% AA/Black; Education: 31.2%≤ high school; Employment: 30.1% unemployed | Baseline tobacco smokers were half as likely as non-tobacco smokers to achieve cannabis abstinence during treatment (OR=0.52, 95% CI: 0.31-0.88, P=0.008), but there was no tobacco-by-treatment interaction (P=0.883) | Higher rates of abstinence among baseline non-tobacco smokers regardless of treatment group.
Gray, 2012^38^; N=116; Single-site (US); 12 wks | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | No difference in time to dropout by baseline cigarette use. | No difference in time to dropout by baseline cigarette use.
MENTAL HEALTH CONDITIONS
ADHD
McRae-Clark, 2010^29^; N=78; Single site (US); Nov 2005 – Jun 2008; 12-week follow-up; Comorbid ADHD | 39 vs 39; Atomoxetine 100mg/day (or MTD); 4 wks; CM for attendance (nominal); 3 MET sessions in weeks 1-4; UA: 1x week | 80% male; Age: 29.9(10.9); Race: 91% White | No significant difference in reduction of ADHD symptoms or cannabis use reduction (P=0.11) by ADHD severity. | No significant difference in reduction of ADHD symptoms or cannabis use reduction (P=0.11) ADHD severity.
Gray, 2012^38^; N=116; Single-site (US); 12 wks | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | No difference in time to dropout by ADHD diagnosis | No difference in time to dropout by ADHD diagnosis
Other Mental Health Conditions
Levin, 2013^19^; N=103; 2 Sites (US); 12-week follow-up; Comorbid Major Depressive Disorder or Dysthymia | 51 vs 52; 1-week placebo lead-in followed by Venlafaxine 225 mg/day (or MTD); 11 weeks; CM for attendance (transportation; $5-20/visit; 24 visits) and medication adherence ($10/week for returning pill bottles); Weekly CBT/RPT; UA: 2x/week | 73.8% male; Age: approx. 35 years; Race: 45.6% White, 21.3% AA/Black, 26.2% Hispanic, 2.9% Asian, 3.9% Other; Education: 29.2% < high school, Employment: 59.2% unemployed/less than FT | For placebo, decreased in depressive symptoms were related to lower THC levels. With venlafaxine, there was no association. | For placebo, decreased in depressive symptoms were related to lower THC levels. With venlafaxine, there was no association.
Gray, 2012^38^; N=116; Single-site (US); 12 wks | 58 vs 58; NAC 2400mg/day; 8 wks; CM for attendance ($5 for first visit increasing by $2 each consecutive visit, 16 visits) and UA- ($5 for UA- increasing by $2 each consecutive UA 16 visits); Brief weekly cessation counseling | Youth 13 to 21; 73% male; Age: 18.9 (1.5); Race: 83.5% White | No difference in time to dropout by diagnoses of Conduct/Oppositional Defiant Disorder, Major Depressive Disorder, Anxiety Disorders, or any other mental health disorder. | No difference in time to dropout by any mental health disorder.

Abbreviations: AA = African American; ADHD = Attention Deficit Hyperactivity Disorder; CBT = cognitive behavioral therapy; CI = Confidence interval; CM = contingency management; FT = full time; Ln = natural logarithm; MCQ = Marijuana Craving Questionnaire ; MET= Motivational Enhancement Therapy; MD = mean difference; mg = milligrams; MM = medication management; MTD = maximum tolerated dose; NAC = N-acetylcysteine; OR = Odds ratio; P = p-value; PBO = placebo; RPT = relapse prevention therapy; SD = standard deviation; SE = standard error; THC = Tetrahydrocannabinol; UA = urinalysis; US = United States

## Discussion

We identified 23 randomized control trials examining pharmacotherapies for the treatment of CUD. Overall, the evidence base is quite limited because of the relatively small number of studies examining most drug classes, small sample sizes, nearly universal high attrition rates, and other methodological flaws in nearly half the trials. Table 5 provides a high-level summary of the evidence, and Table 6 provides a more detailed summary of evidence findings.

As a drug class, antidepressants were by far the best studied, and they were ineffective. We found moderate strength evidence that antidepressants were less effective than placebo for (2 or more-week) abstinence, and moderate strength evidence that they are not beneficial (studies favored placebo or found no difference) for reducing cannabis use. Interestingly, among this population of subjects with comorbid CUD and major depressive disorder, there was consistently no difference between antidepressants and placebo on the reduction of depressive symptomology. These findings however, may be due to high rates of attrition and doses that were insufficient to experience a clinically significant effect.

Among individuals with CUD we found low to moderate strength evidence that buspirone, cannabinoids, and N-acetylcysteine were not effective for achieving abstinence or reducing cannabis use. There was insufficient evidence to draw conclusions about the effects of antipsychotics, mood stabilizers, and the drugs atomoxetine, aprepitant, and oxytocin.

The only potentially promising medications were the anticonvulsants topiramate and gabapentin, which each improved treatment retention. However, there were only 2 small, unclear-ROB trials, and the strength of evidence was low.

Another area which may deserve further exploration is the use of pharmacotherapy to relieve withdrawal symptoms in those with CUD. We expanded our search to include short term (less than 4-week) studies specifically for this outcome; despite this, we were unable to find adequate literature to draw conclusions. However, we did find low strength evidence that cannabinoids might relieve withdrawal symptoms, though there were important inconsistencies in results across studies.

The high rates of attrition in most studies made it difficult to assess harms, particularly study dropouts due to adverse events. Most trials reported very low rates of dropouts due to adverse events, but given the high rates of drop out, and the often incomplete accounting of reasons for drop out, we could not say with confidence to what extent adverse events may have contributed to attrition.

Table 5 Summary of findings

| Abstinence | Use | Retention | Withdrawal Symptoms | Other | Harms
Antidepressants:; Escitalopram, Fluoxetine, Bupropion, Nefazodone, Venlafaxine, Vilazodone | ★★ | ★★ | ★★ | NA | ★ | ★
Antipsychotics: Clozapine, Ziprasidone | A | Ø | Ø | NA | Ø | Ø
Anxiolytic: Buspirone | NA | ★ | ★ | NA | Ø | ★
Mood Stabilizers: Divalproex Sodium, Lithium Carbonate | Ø | Ø | Ø | Ø | Ø | Ø
Cognitive Enhancing Drug: Atomoxetine | NA | Ø | Ø | NA | Ø | Ø
Cannabinoids: Nabilone, Nabiximols, Dronabinol | ★ | ★ | ★★ | ★ | Ø | ★
Anticonvulsants: Gabapentin, Topiramate | NA | Ø | ★ | Ø | Ø | Ø
Glutamatergic modulator: N-acetylcysteine | Ø | ★★ | ★★ | NA | ★★ | ★
Antiemetic/Antinauseant: Aprepitant | NA | Ø | Ø | NA | NA | NA
Hormone: Oxytocin | NA | Ø | NA | NA | NA | NA

Shading represents the direction of effect: (No color)=Unclear, Green=Evidence of benefit, Gray=No benefit, Red=Favors placebo

Symbols represent the strength of the evidence: NA=No evidence or not applicable, Ø Insufficient, ★Low, ★★ Moderate, ★★★ High

Attrition rates were high in nearly all trials, and the reasons for the high dropout rates are unclear. The one exception was a 12-week trial (N=70) comparing the antidepressant fluoxetine to placebo in adolescents and young adults with moderately severe depression who were also receiving contingency management, cognitive behavioral therapy, and motivation enhancement therapy.^20^ Study retention was over 90% in this trial (though the rate did not differ between the intervention and control groups), but it is unclear why study retention was so much higher in this trial as compared to others. Contingency management for treatment retention was a common co-treatment strategy in many studies; 14 of the 23 trials included contingency management with or without travel reimbursements. Indeed, many trials offered considerably larger monetary incentives for treatment attendance than the high-retention trial and still had substantially lower rates of retention.

Studies examining subpopulations were extremely limited, and all pharmacotherapy/population combinations identified were insufficient to form conclusions.

## Limitations

There are several important limitations to this evidence base beyond the overall paucity of trials and small sample sizes. The assessment of the primary outcomes – cannabis use and abstinence – were complicated by several factors. The majority of the trials included urinalysis testing for THC; however, the frequency of collection varied widely. Although we limited inclusion for trials examining these outcomes to 4 weeks or longer, the fact that THC is detectable in urine for up to a month after last cannabis use in frequent users hampers the ability to quantify relative reductions in use beyond reliance on self-report data. Similarly, the possibility of false positive or negative results, diluted samples, as well as factors like donor hydration, metabolic, and activity status, etcetera, may result in uncertainties in outcomes when using THC/creatinine ratios to determine increases or reductions in use, or abstinence. Finally, currently available urine tests are unable to distinguish among different cannabinoids, which complicates studies of cannabinoids for the treatment of CUD.

There was substantial variation in the types of co-interventions used in these studies. Many, but not all, studies included some form of concomitant behavioral or contingency management treatment. We are unable to comment on differential effects of various drugs according to co-interventions used, given the variety of drugs studied and the differences in co-intervention strategies.

For studies examining subpopulation differences, we were unable to form conclusions due to the lack of studies examining similar pharmacotherapies and outcomes. In addition, among included studies of subpopulations, it is possible that the lack of positive findings may reflect small samples and the lack of power to detect differences.

Our review adds to, and differs slightly from, a previous systematic review which concluded with moderate strength evidence that cannabinoids were more effective than placebo for study retention.^1^ More recent trials have reported poorer retention, and we found moderate strength evidence that there is no difference between cannabinoids and placebo.

## Research Gaps/Future Research

There are many areas ripe for further research in this field. As described above, further research on the effectiveness of certain potentially promising drug classes such as the anticonvulsants and cannabinoids is needed before these could be recommended for clinical practice. Given the change in the legal status of cannabis in many states, studies should assess outcomes beyond abstinence, use, withdrawal symptoms, and study retention, and include those related to function and changes in high-risk behaviors. The treatment of withdrawal symptoms in those with cannabis use disorder should be further studied as well. In addition, the lack of reduction in depressive symptoms among those with comorbid CUD and MDD treated with antidepressants should be explored. Finally, identification of subpopulations in which treatment retention might be higher, or in whom certain medications might be more effective, is needed. We did not find adequate evidence to comment on this issue.

## Implications for the VHA

Our findings have a number of implications for the VHA. They will be used to help guide future Health Services Research and Development (HSR&D) priorities. However, the current lack of effective pharmacotherapies leave Veterans seeking treatment for CUD reliant on psychotherapeutic options that can be time-consuming, and less accessible for some (eg, Veterans living in rural areas). These factors may hinder treatment utilization and adherence – thus reinforcing the need to emphasize efforts that increase the accessibility of mental health services for Veterans. With the increased acceptance of cannabis use in the community,^2^ changes in its potency,^3^ and low rates for treatment seeking for CUD,^7^ it is especially important that clinicians be prepared to discuss potential risks of use and assess for potential CUD.

## Conclusion

There is limited research examining the effectiveness of pharmacotherapies for CUD, and many of the existing studies are hampered by poor methodological quality or reporting. There is moderate strength evidence that antidepressants do not reduce cannabis use or improve treatment retention, and may be associated with lower rates of abstinence. There is low to moderate strength evidence that buspirone, and N-acetylcysteine do not improve outcomes. Although we found that cannabinoids do not improve retention, increase rate of abstinence, or reduce cannabis use, we did find low strength evidence that they may reduce withdrawal symptoms. We found insufficient evidence to comment on effects of all other drug classes. Given the increasing access to and use of cannabis in the general population (including Veterans), along with the high prevalence of cannabis use disorder among current cannabis users, there is an urgent need for more research to identify effective pharmacologic treatments.

Conclusions Table Summary of the evidence on pharmacotherapies for cannabis use disorder, stratified by drug class

Treatment; Outcomes | N studies per outcome; ROB (N=combined participants) | Findings on abstinence, drug use, study retention, cannabis withdrawal symptoms, dropout due to AE, serious AEs, and other | Strength of Evidence^*^ | Comments and rationale for strength of evidence rating
PSYCHOPHARMACOTHERAPIES
Antidepressants: Escitalopram, Fluoxetine, Bupropion, Nefazodone, Venlafaxine, Vilazodone
Abstinence | 2 low-ROB RCT^19,21^ (N=209); and 1 high-ROB RCT^22^ (N=52) Total N=261 | Favors placebo: RR=0.49 (95% CI: 0.30 to 0.83); P=0.007 | Moderate | Consistent results across 3 trials of 4 medications.
Use | 3 low-ROB^18–20^ Total N=249 | No benefit: Two trials found no difference between groups, and 1 trial found higher THC levels with venlafaxine. | Moderate | Consistent results of no benefit across trials. Limitations of studies include incomplete outcome data and high rates of attrition.
Retention | 4 low-ROB RCTs^18–21^ (N=355); and 2 high-ROB RCTs^22,23^ (N=74) Total N = 429 | No benefit: RR=0.95 (95% CI: 0.85 to 1.07); P=0.40 | Moderate | Consistent results across trials. Precise estimate.
Dropouts due to AEs/Serious AEs | 3 low-ROB RCTs^18,20,21^ (N=252); and 1 high-ROB RCT^22^ (N=52) Total N=304 | No benefit: Three low-ROB and 1 high-ROB RCT found no difference in the number and severity of AEs or study dropouts due to serious AEs or AEs. Most studies have high rates of attrition, but findings are consistent in 1 study with very low rates of attrition | Low | Consistent finding across trials. Downgraded SOE due to high; attrition and lack of clarity related to reasons for dropout.
Other Outcomes | 4 low-ROB RCTs^18–21^ (N=355); and 2 high-ROB RCTs^22,23^ (N=74) Total N=429 | No benefit: Overall there were no effects of antidepressant medications on secondary outcomes. | Low | Outcomes measured varied across studies and high rates of; attrition across studies
Antipsychotics: Clozapine, Ziprazadone
■ Use | 1 high-ROB RCT^24^ (N=30) | One high-ROB head to head trial found that both ziprasidone and clozapine reduced the frequency of cannabis consumption in subjects with a comorbid psychotic spectrum disorder. There was no difference in reduction between groups. | Insufficient | Small single study. High attrition.
■ Retention | 1 high-ROB RCT^24^ (N=30) | One high-ROB head to head trial found high rates of attrition in both groups, with no significant difference between groups. | Insufficient | Small single study. High attrition.
■ Dropouts due to AEs/Serious AEs | 1 high-ROB RCT^24^ (N=30) | One high-ROB head to head trial found that clozapine was associated with more AEs – specifically hypersalivation (F=8.2; P=0.017). | Insufficient | Small single study. High attrition.
■ Other Outcomes | 1 high-ROB RCT^24^ (N=30) | [underlined: Treatment compliance]: One high-ROB head-to-head trial found more regular group therapy attendance among the ziprasidone group (P=0.024).; [underlined: Drug attitude]: One high-ROB head-to-head trial found that ziprasidone was associated with and a higher drug attitude inventory score (P=0.005).; [underlined: Other mental health:] One high-ROB head-to-head trial found that positive symptoms decreased in both groups, with a stronger decline with clozapine (P=0.05), and that subjects receiving ziprasidone requested a higher number of emergency sessions (P=0.022). | Insufficient | Small single study. High attrition.
Anxiolytic: Buspirone
Use | 1 low-ROB RCT^25^ (N=175); and 1 unclear-ROB RCT^26^ (N=93) Total N=268 | No benefit: In 1 low-ROB and 1 unclear-ROB RCT, there were no differences in odds of weekly abstinence between buspirone and placebo. | Low | Consistent results across 2 trials with high rates of attrition
Retention | 1 low-ROB RCT^25^ (N=175); and 1 unclear-ROB RCT^26^ (N=93) Total N=268 | No benefit: RR=0.92 (95% CI: 0.71 to 1.19); P=0.52 | Low | Consistent results across 2 trials with high rates of attrition
Dropouts due to AEs/Serious AEs | 1 low-ROB RCT^25^ (N=175); and 1 unclear-ROB RCT^26^ (N=93) Total N=268 | No benefit: One low-ROB and 1 unclear-ROB RCT found no differences in the number and severity of AEs or serious AEs. | Low | Low rate of adverse events
Other Outcomes | 1 low-ROB RCT^25^ (N=175); and 1 unclear-ROB RCT^26^ (N=93) Total N=268 | One low-ROB RCT found that cannabis craving decreased for both groups during treatment, but did not differ by condition. A unclear-ROB RCT found that cannabis craving did not significantly change during treatment and there was no difference between groups. | Insufficient | Inconsistent results across 2 trials with high rates of attrition
Mood Stabilizers: Lithium Carbonate, Divalproex Sodium
■ Abstinence | 1 high-ROB RCT^28^; (N=25); and 1 low-ROB RCT^27^ (N=31); Total N=56 | 1 high-ROB RCT reported no difference in end of treatment abstinence (divalproex vs placebo), and a low-ROB RCT found no difference in post-withdrawal abstinence (lithium vs placebo). | Insufficient | Consistent findings across 2 small studies. High attrition.
■ Use | 1 high-ROB RCT^28^; (N=25); and 1 low-ROB RCT^27^ (N=31); Total N=56 | 1 high-ROB RCT and1 low-ROB RCT reported no difference in between lithium and divalproex respectively vs placebo in frequency or quantity of end of treatment/post withdrawal use. | Insufficient | Consistent findings across 2 small studies. High attrition.
■ Retention | 1 high-ROB RCT^28^; (N=25); and 1 low-ROB RCT^27^ (N=31); Total N=56 | RR=1.07 (95% CI: 0.79 to 1.44), P=0.68 | Insufficient | Consistent findings across 2 small studies. High attrition. Imprecise estimate.
■ Dropouts due to AEs/Serious AEs | 1 high-ROB RCT^28^; (N=25); and 1 low-ROB RCT^27^ (N=31); Total N=56 | One low-ROB RCT found no difference in the number and severity of AEs, with no dropouts due to AEs or reported serious AEs. | Insufficient | Single small study. High attrition.
■ Cannabis Withdrawal Symptoms | 1 high-ROB RCT^28^; (N=25); and 1 low-ROB RCT^27^ (N=31); Total N=56 | 1 high-ROB RCT found no difference in craving or irritability; (divalproex vs placebo). A low-ROB RCT found no difference in withdrawal severity, but that lithium was more effective for attenuating nightmares, loss of appetite, and stomach aches. | Insufficient | Consistent findings across 2 small studies. High attrition.
■ Other Outcomes | 1 low-ROB RCT^27^ (N=31) | [underlined: Quality of Life]: One low-ROB RCT found greater physical health but not psychological health or social relations improvement with lithium vs placebo.; [underlined: Severity of Dependence]: One low-ROB RCT found no difference between lithium and placebo.; [underlined: Cannabis Problems]: One low-ROB RCT found no difference between lithium and placebo. | Insufficient | Single small study. High attrition.
■ Other Outcomes | 1 high-ROB RCT^28^ (N=25) | [underlined: Medication Compliance]: One high-ROB RCT suggests lower rates of medication compliance associated with divalproex, but there was no statistical analysis. | Insufficient | Single small study. High attrition.
Cognitive-Enhancing: Atomoxetine
Use | 1 unclear-ROB RCT^29^; (N=78) | No difference in week 12 mean self-reported use, UA results, or % of days used by group. | Insufficient | Single small study. High attrition.
Retention | 1 unclear-ROB RCT^29^; (N=78) | No difference | Insufficient | Single small study. High attrition.
Dropouts due to AEs/Serious AEs | 1 unclear-ROB RCT^29^; (N=78) | No difference | Insufficient | Single small study. High attrition.
Other | 1 unclear-ROB RCT^29^; (N=78) | CGI improved. No difference in change in ADHD severity. Greater rate of ADHD symptom decline in weeks 1-4, but there was no subsequent difference between groups. No difference in heavy use days. | Insufficient | Single small study. High attrition.
CANNABINOIDS: Dronabinol, Nabilone, Nabiximols
■ Abstinence | 1 low-ROB RCT^30^ (N=156); and 1 unclear-ROB RCT^31^ (N=122) Total N =278 | No benefit (Dronabinol): RR=1.07 (95% CI: 0.65 to 1.76); P=0.80 | Low | Consistent findings across studies. Outcomes based on self-report, high rates of attrition.
■ Use | 2 low-ROB RCTs^30,34^ (N=207); and 2 unclear-ROB RCT^32,33^ (N=58) Total N=265 | No benefit: Two low-ROB RCTs and 2 unclear-ROB RCTs found no difference in reduction in use between groups. | Low | Consistent findings across studies. Outcomes based on self-report, high rates of attrition.
■ Retention | 2 low-ROB RCTs^30,34^ (N=207); and 3 unclear-ROB RCTs^31–33^ (N=180) Total N=387 | No benefit: RR=1.06 (95% CI: 0.89 to 1.25); P=0.53 | Moderate | Consistent findings across 4/5 studies. Outcomes based on self-report, high rates of attrition.
■ Dropouts due to AEs/Serious AEs | 2 low-ROB RCTs^30,34^ (N=207); and 1 unclear-ROB RCT^31^ (N=122) Total N=329 | No benefit: High rates of attrition make it difficult to evaluate rates of dropout to adverse events. Of studies that reports dropouts due to AE no significant differences were reported between groups. One low-ROB placebo-controlled trial reported no dropouts to AEs; Two low-ROB RCTs reported similar SAEs. | Low | Consistent findings across studies. Downgraded SOE due to high attrition and lack of clarity related to reasons for dropout.
■ Cannabis Withdrawal Symptoms | 2 low-ROB RCT^30,34^ (N=207); and 3 unclear-ROB RCTs^31–33^ (N=180) Total N=387 | Favors cannabinoids: Two low-ROB RCTs found that cannabinoids significantly reduce withdrawal symptoms.; Three unclear-ROB RCTs found no treatment effect. | Low | Downgraded due to inconsistent findings across studies, although overall findings, including of high quality studies, favor treatment.
■ Other Outcomes | 2 unclear-ROB RCTs^32,33^ (N=58) | [underlined: Craving]: One unclear-ROB trials found no difference between treatment groups. One unclear-ROB trial found decreased craving for treatment group.; [underlined: Anxiety]: No difference. One unclear-ROB study reported no treatment effect on anxiety. | Insufficient | Inconsistent findings and different outcomes evaluated.
OTHER PHARMACOTHERAPIES
Anticonvulsants: Gabapentin, Topiramate
■ Use | 2 unclear-ROB RCTs^35,36^ (N=116); and 1 unclear-ROB RCT^36^ (N=50); Total N=166 | One RCT found more UA(-) with gabapentin vs placebo. The second found no difference between topiramate and placebo in UA(-) or change in UA results in weeks 1-6. | Insufficient | Inconsistent findings across trials. Applicability limited due to younger sample in topiramate study.
■ Retention | 2 unclear-ROB RCTs^35,36^ (N=116); and 1 unclear-ROB RCT^36^ (N=50); Total N=166 | Favors topiramate and gabapentin: 2 unclear-ROB RCTs found significantly higher retention for both topiramate and gabapentin vs placebo. | Low | Consistent findings across 2 trials.
■ Dropouts due to AEs/Serious AEs | 2 unclear-ROB RCTs^35,36^ (N=116); and 1 unclear-ROB RCT^36^ (N=50); Total N=166 | High rates of attrition make it difficult to evaluate rates of dropout to adverse events. 1 RCT found a higher rate of dropouts due to AEs with topiramate. The second found no difference between gabapentin and placebo. No differences were reported in SAEs. | Insufficient | Inconsistent findings across 2 trial and high rates of attrition.
■ Cannabis withdrawal | 1 unclear-ROB RCT^36^ (N=50) | 1 RCT found greater improvement in cannabis withdrawal symptoms (including sleep symptoms) with GAB | Insufficient | Inconsistent findings across 2 trials. Applicability limited due to younger sample in topiramate study.
■ Other | 2 unclear-ROB RCTs^35,36^ (N =116) | [underlined: Depressive symptoms]: 1 RCT found greater improvement with gabapentin. The other found no difference in overall symptom scores, but a greater reduction in symptoms with placebo than topiramate.; [underlined: Neurocognitive performance]: One RCT found greater improvement with GAB. The second found decreased retrieval performance and memory with topiramate.; [underlined: Medication compliance]: Two RCTs found no difference for GAB or topiramate vs placebo | Insufficient | Inconsistent findings across 2 trials. Applicability limited due to younger sample in topiramate study.
■ Other | 1 unclear-ROB RCT^36^ (N=50) | [underlined: Craving]: One RCT found greater reduction with GAB (P<0.001); [underlined: Cannabis-related consequences]: One RCT found greater reductions with GAB (P=0.02); [underlined: Cannabis related problems]: One RCT found greater improvement with GAB on psychological and physical cannabis-related problems. | Insufficient | Single small study.
Glutamatergic Modulator: N-acetylcysteine
■ Abstinence | 1 low-ROB RCT^38^ (N=116) | 1 low-ROB RCT^38^ found a non-significant trend towards 2-week end-of-trial abstinence favoring NAC. | Insufficient | Applicability due to adolescent sample, single study.
■ Use | 2 low-ROB RCTs^37,38^ (N=418) | No benefit: 2 low-ROB RCTs found no difference in use (RR=1.22, 95% CI [0.81 – 1.83], P=0.35) | Moderate | Consistent findings across trials. Applicability due to age differences in study populations. High rates of attrition
■ Retention | 2 low-ROB RCTs^37,38^ (N=418) | No benefit: 2 low-ROB RCTs found no difference in treatment retention. Combined RR=1.08, 95% CI [0.95 – 1.23], P=0.25. | Moderate | Consistent findings across trials. Applicability due to age differences in study populations. High rates of attrition
■ Dropouts due to AEs; ■ Serious AEs | 2 low-ROB RCTs^37,38^ (N=418) | No benefit: High rates of attrition make it difficult to evaluate rates of dropout to adverse events. 2 low-ROB RCTs found no difference on harms in dropouts due to AE or SAEs. | Low: dropouts due to AEs; Low: SAEs | Consistent findings across trials. Applicability due to age differences in study populations. High rates of attrition
Other | 2 low-ROB RCTs^37,38^ (N=418) | [underlined: Medication adherence]: No benefit: 2 low-ROB RCTs found no difference in medication adherence | Moderate | Consistent findings across trials. Applicability due to age differences in study populations. High rates of attrition
Antiemetic/Antinauseant: Aprepitant
■ Use | 1 unclear-ROB RCT^39^ (N=20) | Greater change in urinary CN-THCCOOH Levels from week; 0 to 8 with aprepitant [Units: ng/mg]: 198.3 (SD=389.4) vs; 55.9 (SD=239.3); No statistical analysis provided | Insufficient | Single study, low power, not yet published
■ Retention | 1 unclear-ROB RCT^39^ (N=20) | Poorer retention in aprepitant group than placebo group. No statistical analysis provided | Insufficient | Single study, low power, not yet published
Hormone: Oxytocin
■ Use | 1 high-ROB RCT^40^ (N=16) | One high-ROB trial found no significant differences in Oxytocin compared to placebo. | Insufficient | Lack of blinding, many-ROB factors not reported, low power.

Abbreviations: ADHD = Attention Deficit Hyperactivity Disorder; AE = Adverse event; CI = Confidence interval; CN-THCCOOH = creatinine normalized 11-nor-9-carboxy-Δ9-tetrahydrocannnabinol; DRO = Dronabinol; DSM = Diagnostic and Statistical Manual of Mental Disorders; GAB= gabapentin; MD = mean difference; mg = milligram; NAC = N-acetylcysteine; ng = nanogram; NR = no response; P = p-value; PBO = placebo; RCT = randomized control trial; RD = risk difference; RR = Risk ratio;-ROB = Risk of bias; SAE = serious adverse event; SMD = standard mean difference; SSRI = Selective Serotonin Reuptake Inhibitors; SR = Systematic review; THC = Tetrahydrocannabinol; UA = urinalysis

* The overall quality of evidence for each outcome is based on the consistency, coherence, and applicability of the body of evidence, as well as the internal validity of individual studies. The strength of evidence is classified as follows:^17^

High = Further research is very unlikely to change our confidence on the estimate of effect.

Moderate = Further research is likely to have an important impact on our confidence in the estimate of effect and may change the estimate.

Low = Further research is very likely to have an important impact on our confidence in the estimate of effect and is likely to change the estimate.

Insufficient = Any estimate of effect is very uncertain.