# Methods

## Topic Development

The research questions for this systematic review were nominated by Dr. Dominick DePhilippis, Education Coordinator at the Philadelphia CESATE, in conjunction with Dr. Karen Drexler, National Mental Health Program Director, Substance Use Disorders for the Office of Mental Health Services, and were developed after a topic refinement process that included a preliminary review of published peer-reviewed literature, and consultation with internal partners, investigators, and stakeholders. The Key Questions are as follows:

KQ1 What are the benefits and harms of pharmacotherapy for cannabis use disorder?
KQ2 Are there known subpopulations for whom currently used pharmacotherapy is most/least effective for cannabis use disorder?

Our approach was guided by a conceptual framework developed in consultation with our operational partners (see Figure 1). A protocol describing the review plan was posted to a publicly accessible website before the study was initiated.^11^

## Search Strategy

To identify evidence examining pharmacotherapy for cannabis use disorder, we independently evaluated and abstracted studies included in a 2014 systematic review of pharmacotherapies for cannabis dependence.^1^ In addition, we conducted a search of Ovid MEDLINE, OvidPsycINFO, and Ovid EBM Reviews Cochrane Database of Systematic Reviews (CDSR, DARE, HTA, Cochrane CENTRAL, etc) for studies published after the prior review^1^ (January 2014 to July 2018) as well as ClinicalTrials.gov, OpenTrials, and the World Health Organization (WHO) International Clinical Trials Registry Platform (ICTRP). Search strategies were developed in consultation with a research librarian, and were peer reviewed by a second research librarian using the instrument for Peer Review of Search Strategies (PRESS; see Appendix A).^12^

## Study Selection

We included studies that directly compared pharmacological interventions against each other, placebo, usual care, or psychotherapy in adults and adolescents with cannabis use disorders. We examined only randomized controlled trials (RCTs). We used a “best evidence” approach to guide additional study design criteria depending on the question under consideration and the literature available.^13^ To address concerns related to the detection window for THC, we limited inclusion to studies of 4 weeks or longer for all outcomes except withdrawal symptoms (see Appendices B and C and Table 1).

Two independent reviewers evaluated titles, abstracts, and relevant full-text articles for inclusion. All discordant results were resolved through consensus or consultation with a third reviewer.

## Data Abstraction and Quality Assessment

Data from studies meeting inclusion criteria were abstracted by 1 investigator and were confirmed by a second. Two reviewers independently assessed the risk of bias (ROB) of each study using a tool developed by the Cochrane Collaboration (Appendix C).^14,15^ Disagreements were resolved by consensus or a third reviewer.

## Data Synthesis and Analysis

We qualitatively synthesized the evidence for each key question, and conducted meta-analyses when combinable outcomes were reported among studies of the same drug or drug class. When meta-analysis was performed, we used a random effects model of analysis. Meta-analyses were performed using RevMan 5.3 software.^16^ For trials reporting both intent-to-treat (ITT) analyses and modified ITT analyses (eg, subjects who received the study drug/placebo, or for whom at least 1 outcome was assessed), we examined both. Our synthesis is based on ITT analyses when provided, and we report differences between the 2 methods only when they impacted our conclusions. We assessed the overall strength of evidence (SOE) for each outcome using an established method that takes into consideration a range of factors (eg, study quality, consistency of findings, directness of the comparisons, applicability), and classified SOE as high, moderate, low, or insufficient.^17^ For findings for which the SOE was not insufficient, we classified the direction of effects as evidence of benefit, no benefit (ie, no difference from placebo or mixed findings of no difference from placebo and favors placebo), and favors placebo.

Figure 1 Analytic Framework

Table 1 PICOTS by Key Question

Key Question: | KQ1: What are the effectiveness and harms of pharmacotherapies (with or without concurrent psychosocial treatment) for cannabis use disorder? | KQ2: Are there known subpopulations for whom currently used pharmacotherapy is most/least effective?
Population | Included: Non-pregnant adults and adolescents with known or suspected cannabis use disorder.; Excluded: Children and pregnant adults. | Subpopulations may include:; - Demographic factors; - Addiction severity; - Comorbid mental and substance use disorders (eg, HIV, mood and anxiety disorders, psychotic disorders, ADHD, alcohol use, stimulant use, opioid use/methadone maintained); - Other clinical conditions (eg, pain, sleep disorders)
Intervention | Included: Pharmacotherapies identified as a potential treatment for cannabis use disorder with or without adjunctive treatment (eg, medication management; interpersonal therapy; contingency management [or motivational incentives]; CBT [including matrix therapy, relapse prevention]).; Excluded: Pharmacotherapies intended to treat other conditions.
Comparators | Usual care, placebo, or other interventions (comparison groups must receive the same adjunctive treatments)
Outcomes | - Intermediate/Behavioral outcomes; - Abstinence/Reduction of cannabis use (eg, quantitative urine levels; validated self-report measures [ie, TimeLine Follow Back, ASI, diagnostic interviews]); - Severity of withdrawal symptoms; - Retention in treatment; - Health outcomes; - Morbidity/mortality; - Quality of life; - Harms; - Dropout due to AE, and serious AE (as reported)
Timing | Minimum study duration (including follow-up) 4 weeks. Except for studies of withdrawal
Settings | - Outpatient; - Inpatient; - Incarceration/detention centers, correctional facilities
Study design | - Randomized controlled trials.

Abbreviations: ADHD = Attention Deficit Hyperactivity Disorder; AE = adverse event; ASI = Addiction Severity Index; CBT = cognitive behavioral therapy; HIV = Human immunodeficiency virus