# Executive Summary

[underlined: Aim:] We conducted a systematic review and meta-analysis of the benefits and risks associated with the use of various pharmacotherapies for the achievement of abstinence, the promotion of cessation or reduction of cannabis use, and retention among individuals with cannabis use disorder (CUD).

[underlined: Methods:] We searched electronic databases, clinical trial registries, and reference lists through July 2018 for randomized controlled trials (RCTs) directly comparing pharmacological interventions against each other, placebo, usual care, or psychotherapy in individuals with CUD. We abstracted data on study design, interventions, and outcomes. Dual assessment of study’s full text, quality, and strength of evidence (SOE) was agreed upon by consensus using published criteria.

[underlined: Results:] We included 23 primary studies. Antidepressants were the most widely studied drug class. We found moderate SOE that subjects receiving antidepressants are less likely to achieve abstinence than those randomized to placebo, that antidepressants are not beneficial in reducing overall cannabis use, and that there is no difference from placebo in study retention (combined RR=0.95, 95% CI: 0.85-1.07). We found no difference between antidepressants and placebo in dropouts due to serious adverse events (low SOE). In addition, we found no difference between cannabinoids and placebo in the achievement of abstinence (low SOE), treatment retention (combined RR=1.06, 95% CI: 0.89 to 1.25; moderate SOE), and reduction in cannabis use (low SOE). We did find low strength evidence that cannabinoids may result in a greater reduction in cannabis withdrawal symptoms. Anticonvulsants may improve study retention (low SOE); the evidence for anticonvulsants on other outcomes is insufficient. We found low to moderate strength evidence that buspirone and N-acetylcysteine do not improve outcomes. There was insufficient evidence for most other drug classes examined.

[underlined: Conclusion:] There is limited research examining the effectiveness of pharmacotherapies for CUD, and many of the existing studies are hampered by poor methodological quality or reporting. There is moderate strength evidence that antidepressants do not reduce cannabis use or improve treatment retention, and may be associated with lower rates of abstinence. There is low to moderate strength evidence that buspirone, and N-acetylcysteine do not improve outcomes. Although we found that cannabinoids do not improve retention, increase rate of abstinence, or reduce cannabis use, we did find low strength evidence that they may reduce withdrawal symptoms. We found insufficient evidence to comment on effects of all other drug classes. Given the increasing access to, and use of, cannabis in both the general and Veteran populations, along with the high prevalence of CUD among current cannabis users, there is an urgent need to identify novel interventions and effective pharmacologic treatments.

## Abbreviations Table

Abbreviation: Term
AA: African American
ADHD: Attention Deficit Hyperactivity Disorder
AE: Adverse event
AHRQ: Agency for Healthcare Research and Quality
AU: Australian
BAI: Beck Anxiety Inventory
BBCET: Brief Behavioral Compliance Enhancement Treatment
C: Control group
Can: Canadian
CBD: Cannabidiol
CBT: Cognitive behavioral therapy
CGI: Clinical Global Impressions
CI: Confidence interval
CM: Contingency management
CN-THCCOOH: creatinine normalized 11-nor-9-carboxy-Δ9-tetrahydrocannnabinol
CUD: Cannabis use disorder
DRO: Dronabinol
DSM: Diagnostic and Statistical Manual of Mental Disorders
EBM: Evidence-based Medicine
EPC: Evidence-based Practice Center
ESP: Evidence Synthesis Program
FDA: Food and Drug Administration
FT: Full time
GAB: gabapentin
HAM-D: Hamilton Depression Rating Scale
hr: Hour
HR: Hazard ratio
HSR&D: Health Services Research and Development Service
ITT: Intention-to-treat
IU: International unit
KQ: Key question
Ln: Natural logarithm
MA: Meta-analysis
MCQ: Marijuana Craving Questionnaire
MD: Mean difference
MDD: Major depressive disorder
MET: Motivation Enhancement Therapy
mg: Milligram
min: Minutes
MM: Medication management
MTD: Maximum tolerated dose
NA: Not applicable
NIH: National Institutes of Health
NR: Not reported
NS: Not significant
OR: Odds ratio
P: P-value
PBO: Placebo
PICOTS: Population, interventions, comparators, outcomes, timing, and setting
PRN: As needed
QUERI: Quality Enhancement Research Initiative
RCT: Randomized controlled trial
RD: Risk difference
ROB: Risk of bias
RPT: Relapse prevention therapy
RR: Relative risk
SAE: Serious adverse event
SD: Standard deviation
SE: Standard error
SEM: Standard error of the mean
SERT: Sertraline
SES: Socioeconomic status
Sig: Statistically significant
SMD: standard mean difference
SNRI: Serotonin and Norepinephrine Reuptake Inhibitor
SOE: Strength of evidence
SR: Systematic review
SSRI: Selective Serotonin Reuptake Inhibitors
SUD: Substance use disorder
TEP: Technical expert panel
THC: Tetrahydrocannabinol
TLFB: Timeline Follow-back Interview
T: Treatment group
UA: Urinalysis
US: United States
VHA: Veterans’ Health Administration
wk: Week
yr: Year