# APPENDIX D Quality Assessment of Included Studies

Author, year | Sequence generation | Allocation concealment | Blinding | Incomplete outcome data | Selective outcome reporting | Other sources of bias | Risk of Bias
Allsop, 2014[underlined: 34] | Yes | Yes | Yes | Yes | Yes | Yes | Low
Carpenter, 2009^21^ | Unclear | Yes | Yes | Yes | Yes | Yes | Low
Cornelius, 2010^20^ | Yes | Unclear | Yes | Yes | Yes | Yes | Low
Gray, 2012^38^ | Unclear | Yes | Yes | Yes | Yes | Yes | Low
Gray, 2017^37^ | Yes | Yes | Yes | Yes | Yes | Yes | Low
Hill, 2017^32^ | Unclear | Unclear | Unclear | Yes | Yes | Yes | Unclear
Johnston, 2014^27^ | Yes | Yes | Yes | Yes | Yes | Yes | Low
Levin, 2004^28^ | Unclear | Unclear | Unclear | Unclear | Yes | Unclear | High
Levin, 2011^30^ | Yes | Yes | Yes | Yes | Yes | Yes | Low
Levin, 2013^19^ | Yes | Yes | Yes | Unclear | Yes | Yes | Low
Levin, 2016^31^ | Unclear | Unclear | Yes | Yes | Yes | Unclear | Unclear
Mason, 2012^36^ | Yes | Yes | Yes | Unclear | Yes | Unclear | Unclear
McRae-Clark, 2009^26^ | Yes | Unclear | Unclear | Yes | Yes | Unclear | Unclear
McRae-Clark, 2010^29^ | Unclear | Unclear | Yes | Unclear | Yes | Yes | Unclear
McRae-Clark, 2015^25^ | Yes | Yes | Yes | Yes | Yes | Yes | Low
McRae-Clark, 2016^18^ | Yes | Yes | Yes | Yes | Yes | Yes | Low
Miranda, 2017^35^ | Yes | Yes | Yes | Yes | Yes | Unclear | Unclear
The Scripps Research Institute^39^ | Unclear | Unclear | Yes | Unclear | Unclear | Unclear | Unclear
Penetar, 2012^23^ | Unclear | Unclear | Yes | Unclear | Unclear | No | High
Schnell, 2014^24^ | Yes | Yes | No | No | Yes | No | High
Sherman, 2017^40^ | Unclear | Unclear | Unclear | No | Unclear | Unclear | High
Trigo, 2018^33^ | Unclear | Yes | Yes | Unclear | Yes | Yes | Unclear
Weinstein, 2014^22^ | Unclear | Unclear | Yes | Unclear | Yes | No | High

Yes = adequately addressed; Unclear = unclear or not reported; No = not adequately addressed