# APPENDIX C Quality Assessment Criteria

Domain | Criteria ^15^
Sequence generation | Was the allocation sequence adequately generated?
Allocation concealment | Was allocation adequately concealed?
Blinding | Was knowledge of the allocated intervention adequately prevented during the study?
Incomplete outcome data | Were incomplete and missing outcome data adequately addressed?
Selective outcome reporting | Are reports of the study free of suggestion of selective outcome reporting?
Other sources of bias | Was the study apparently free of other problems that could put it at a high risk of bias?
Overall assessment of potential for bias | Low/Unclear/High

Risk of Bias | Interpretation | Within a Trial
Low | Bias, if present, is unlikely to alter the results seriously | Low risk of bias for all key domains
Unclear | A risk of bias that raises some doubt about the results | Low or unclear risk of bias for all key domains
High | Bias may alter the results seriously | High risk of bias for one or more key domains