# APPENDIX B Study Selection

## Inclusion codes, code definitions, and criteria

1. Is the population made up of non-pregnant/non-postpartum adolescents and/or adults with known or suspected cannabis use disorder?
  - Yes → Proceed to 2.
  - No → STOP. Code X1 (Excluded population)
2. Does the intervention include pharmacotherapy to treat cannabis use disorder?
  Exclude: Pharmacotherapies intended to treat comorbid substance dependence (eg, stimulants, alcohol or heroin) rather than cannabis use.
  - Yes → Proceed to 3.
  - No → STOP. Code X2 (Not relevant to topic)
3. Is the study design a randomized controlled trial with follow-up of 4 weeks or longer (unless the outcome being examined is withdrawal, in which case shorter studies are acceptable)?
  - Yes → Proceed to 4.
  - No → STOP. Code X3 (Excluded study design or publication type)
  Exclude: Narrative or non-systematic review; opinion/editorial; cross-sectional study; case report/case series; case-control; cohort study; conference proceeding Also exclude RCTs that compare dosage levels of the same drug, without a placebo group or other active comparator. Duration of less than 4 weeks for studies of abstinence/reduction in use.
  Note: Systematic reviews, meta-analyses, and other important background/discussion papers should be coded B-X3, followed by notes/keywords.
  Examples:
  - B-X3 – SR, pearl references
  - B-X3 – narrative review with good background
  - B-X3 – useful for discussion
  - B-X3 – conference proceeding potentially useful
4. Does the study measure cannabis abstinence and/or use by urinalysis and/or validated self-report scale (ie, TimeLine Follow Back, ASI, ASSIST, DAST, SCID, DIS, MINI, results of diagnostic interviews)? AND/OR Does it measure withdrawal with validated measures (eg, Cannabis Withdrawal Scale, Drug Effects Questionnaire (DEQ), Marijuana Withdrawal Checklist (MWC); Marijuana Craving Questionnaire± Short Form (MCQ-SF)).
  - Yes → Proceed to 5.
  - No → STOP. Code X4 (No outcomes of interest)
  Note: We will not analyze the following outcomes:
  - Outcomes with lack of clinical implication (eg, brainwave Stroop)
5. Do all study arms receive identical treatment with the exception of the medication being tested? For example, if the active arm receives psychotherapy, the comparator arm should receive an identical form of psychotherapy with the same frequency and level of intensity as the primary arm.
  - Yes → Proceed to 6.
  - No → STOP. Code X5 (Unbalanced study design)
6. Does the comparator arm consist of another active medication for treating cannabis use disorder?
  - Yes → Code H2H. Proceed to 7.
  - No → Code RCT. Proceed to 7.
7. Enter the medication(s) being tested.