# APPENDIX A Search Strategies

Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations, and Daily 1946 to July 17, 2018

Date Searched: July 18, 2018

Searched by: Robin Paynter, MLIS

# | Searches | Results
1 | Marijuana Abuse/dt, th or ((Cannabis/ or Marijuana Smoking/) and (Drug Dependency/dt, th or Substance Related Disorders/dt, th)) | 630
2 | ((cannabis or canabis or cannabacae or marijuana or marihuana or hashish or hash or ganja or ganjah or hemp or bhang or charas) adj3 (abuse* or abusing or addict* or chronic* or daily or disorder* or depend* or habitual* or heavy or misuse* or overuse or quit*)).tw,kf. | 4367
3 | or/1-2 | 4699
4 | Substance Withdrawal Syndrome/dt, th or exp Inactivation, Metabolic/ or Drug Therapy/ or ae,ai,co,ct,dt,po,th,to.fs. | 40116
5 | (abstain* or abstinen* or craving or detox* or desintox* or medication* or pharmacotherap* or pharmaco-therap* or reduce* or reducing or reduction or relaps* or retain* or retention or sobriety or therap* or treat* or withdraw*).tw,kf. | 8279582
6 | or/4-5 | 8289740
7 | and/3,6 | 2502
8 | randomized controlled trial.pt. | 464336
9 | controlled clinical trial.pt. | 92503
10 | randomized.ti,ab. | 448654
11 | placebo.ti,ab. | 195474
12 | "drug therapy".ti,ab. | 33021
13 | randomly.ti,ab. | 294694
14 | trial.ti,ab. | 508714
15 | groups.ti,ab. | 1838965
16 | or/8-15 | 2713265
17 | and/7,16 | 720
18 | (animals not (humans and animals)).sh. | 4441716
19 | 17 not 18 | 701
20 | limit 19 to yr="2014-Current" | 286

Ovid PsycINFO 1806 to July Week 2 2018

Date Searched: July 18, 2018

# | Searches | Results
1 | (Cannabis/ or Hashish/ or Marijuana/ or Marijuana Usage/) and (Addiction/ or Drug Abuse/ or Drug; Addiction/ or Drug Dependency/ or “Substance Use Disorder”/) | 3014
2 | ((cannabis or canabis or cannabacae or marijuana or marihuana or hashish or hash or ganja or ganjah or hemp or bhang or charas) adj3 (abuse* or abusing or addict* or chronic* or daily or disorder* or depend* or habitual* or heavy or misuse* or overuse or quit*)).tw. | 3996
3 | or/1-2 | 5413
4 | exp Drug Therapy/ or drug withdrawal/ or detoxification/ or drug rehabilitation/ or craving/ or drug abstinence/ | 161862
5 | (abstain* or abstinen* or craving or detox* or desintox* or “drug therap*” or medication* or pharmacotherap* or pharmaco-therap* or reduce* or reducing or reduction or relaps* or retain* or retention or sobriety or “substance withdrawal syndrome” or therap* or treat* or withdraw*).tw. | 1228340
6 | or/4-5 | 1241264
7 | and/3,6 | 2835
8 | Treatment Effectiveness Evaluation/ or exp Treatment Outcomes/ or Placebo/ or Follow-up Studies/ | 71506
9 | (((placebo* or random* or comparative or clinical) adj3 trial*) or (research adj3 design) or ((evaluat* or prospect*) adj3 stud*) or ((singl* or doubl* or trebl* or tripl*) adj3 (blind* or mask*))).ti,ab. | 182379
10 | or/8-9 | 237297
11 | and/7,10 | 534
12 | limit 11 to yr="2014 -Current" | 199

Ovid EBM Reviews Cochrane Central Register of Controlled Trials June 2018, Cochrane Database of Systematic Reviews 2005 to July 11, 2018 Database of Abstracts of Reviews of Effects 1st Quarter 2016 Health Technology Assessment 4th Quarter 2016

Date Searched: July 18, 2018

# | Searches | Results
1 | ((cannabis or canabis or cannabacae or marijuana or marihuana or hashish or hash or ganja or ganjah or hemp or bhang or charas) adj3 (abuse* or abusing or addict* or chronic* or daily or disorder* or depend* or habitual* or heavy or misuse* or overuse or quit*)).tw. | 774
2 | (abstain* or abstinen* or craving or detox* or desintox* or “drug therap*” or medication* or pharmacotherap* or pharmaco-therap* or reduce* or reducing or reduction or relaps* or retain* or retention or sobriety or therap* or treat* or withdraw*).tw. | 824767
3 | 1 and 2 | 639
4 | limit 3 to yr="2014 -Current" [Limit not valid in DARE; records were retained] | 297

ClinicalTrials.gov

Date Searched: July 18, 2018

( cannabis OR canabis or marijuana OR marihuana OR hashish OR hash OR ganja OR ganjah OR hemp OR bhang OR charas ) AND ( abuse* OR abusing OR addict* OR chronic* OR daily OR disorder* OR depend* OR habitual* OR heavy OR misuse* OR overuse OR quit* ) | ( cannabis OR canabis or marijuana OR marihuana OR hashish OR hash OR ganja OR ganjah OR hemp OR bhang OR charas ) | First posted from 01/01/2014 to 07/18/2018

= 92 studies

WHO ICTRP

Date Searched: July 18, 2018

CONDITION: (cannabis OR canabis or marijuana OR marihuana OR hashish OR hash) AND (abuse* OR abusing OR addict* OR chronic* OR daily OR disorder* OR depend* OR habitual* OR heavy OR misuse* OR overuse OR quit*)

INTERVENTION: ("drug therap*" OR medication* OR pharmacotherap* OR pharmaco-therap* OR therap* OR treat*)

RECRUITMENT STATUS: ALL

DATE OF REGISTRATION: 01/01/2018 and 18/07/2018

= 53 results

Open Trials

Date Searched: July 18, 2018

CONDITION: (cannabis OR canabis OR marijuana OR marihuana OR hashish OR hash)

REGISTRATION PERIOD START DATE: 01/01/2014