# REFERENCES

1 Gaskin DJ, Richard P. The economic costs of pain in the United States. J Pain. 2012;13(8):715–24.22607834
2 Dieleman JL, Cao J, Chapin A, . US Health Care Spending by Payer and Health Condition, 1996-2016. Jama. 2020;323(9):863–884.32125402
3 Fransen M, McConnell S, Harmer AR, . Exercise for osteoarthritis of the knee. Cochrane Database of Systematic Reviews. 2015;1:CD004376.25569281
4 Hayden JA, Ellis J, Ogilvie R, . Exercise for treatment of chronic low back pain. Cochrane.org; 2021.
5 Essery R, Geraghty AW, Kirby S, . Predictors of adherence to home-based physical therapies: a systematic review. Disabil Rehabil. 2017;39(6):519–534.27097761
6 Sluijs EM, Kok GJ, van der Zee J. Correlates of exercise compliance in physical therapy. Phys Ther. 1993;73(11):771–82; discussion 783-6.8234458
7 Voils CI, Gierisch JM, Yancy WS, . Differentiating Behavior Initiation and Maintenance: Theoretical Framework and Proof of Concept. Health Education & Behavior. 2013;41(3):325–336.24347145
8 O’Halloran PD, Blackstock F, Shields N, . Motivational interviewing to increase physical activity in people with chronic health conditions: a systematic review and meta-analysis. Clin Rehabil. 2014;28(12):1159–71.24942478
9 Bassett SFPMD. Bridging the intention-behaviour gap with behaviour change strategies for physiotherapy rehabilitation non-adherence. New Zealand Journal of Physiotherapy. 2015;43(3):105–111.
10 Michie S, Richardson M, Johnston M, . The behavior change technique taxonomy (v1) of 93 hierarchically clustered techniques: building an international consensus for the reporting of behavior change interventions. Ann Behav Med. 2013;46(1):81–95.23512568
11 Jordan JL, Holden MA, Mason EE, . Interventions to improve adherence to exercise for chronic musculoskeletal pain in adults. Cochrane Database of Systematic Reviews. 2010(1):CD005956.20091582
12 Page MJ, McKenzie JE, Bossuyt PM, . The PRISMA 2020 statement: an updated guideline for reporting systematic reviews. BMJ. 2021;372:n71.33782057
13 McGowan J, Sampson M, Salzwedel DM, . PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016(1878-5921 (Electronic)).
14 National Institute of Neurological Disorders and Stroke. Low Back Pain Fact Sheet. Vol. 2022: National Institutes of Health; 2021.
15 RoB2 Development Group. Revised Cochrane risk-of-bias tool for randomized trials (RoB 2). Vol. 2022: riskofbias.info; 2019.
16 Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016;355:i4919.27733354
17 Hultcrantz M, Rind D, Akl EA, . The GRADE Working Group clarifies the construct of certainty of evidence. (1878-5921 (Electronic)).
18 Brosseau L, Wells GA, Kenny GP, . The implementation of a community-based aerobic walking program for mild to moderate knee osteoarthritis (OA): a knowledge translation (KT) randomized controlled trial (RCT): Part I: The Uptake of the Ottawa Panel clinical practice guidelines (CPGs). BMC Public Health. 2012;12:871.23061875
19 Ben-Ami N, Chodick G, Mirovsky Y, . Increasing Recreational Physical Activity in Patients With Chronic Low Back Pain: A Pragmatic Controlled Clinical Trial. Journal of Orthopaedic & Sports Physical Therapy. 2017;47(2):57–66.28142364
20 Bennell K, Nelligan RK, Schwartz S, . Behavior Change Text Messages for Home Exercise Adherence in Knee Osteoarthritis: Randomized Trial. Journal of Medical Internet Research. 2020;22(9):e21749.32985994
21 Baker K, LaValley MP, Brown C, . Efficacy of Computer-Based Telephone Counseling on Long-Term Adherence to Strength Training in Elderly Patients With Knee Osteoarthritis: A Randomized Trial. Arthritis care & research. 2020;72(7):982–990.31074576
22 Quicke JG, Foster NE, Ogollah RO, . Relationship Between Attitudes and Beliefs and Physical Activity in Older Adults With Knee Pain: Secondary Analysis of a Randomized Controlled Trial. Arthritis care & research. 2017;69(8):1192–1200.27696795
23 Bennell KL, Kyriakides M, Hodges PW, . Effects of two physiotherapy booster sessions on outcomes with home exercise in people with knee osteoarthritis: a randomized controlled trial. Arthritis care & research. 2014;66(11):1680–7.24757032
24 Lonsdale C, Hall AM, Murray A, . Communication Skills Training for Practitioners to Increase Patient Adherence to Home-Based Rehabilitation for Chronic Low Back Pain: Results of a Cluster Randomized Controlled Trial. Archives of Physical Medicine & Rehabilitation. 2017;98(9):1732–1743.e7.28363702
25 Bennell KL, Campbell PK, Egerton T, . Telephone Coaching to Enhance a Home-Based Physical Activity Program for Knee Osteoarthritis: A Randomized Clinical Trial. Arthritis care & research. 2017;69(1):84–94.27111441
26 Pisters MF, Veenhof C, de Bakker DH, . Behavioural graded activity results in better exercise adherence and more physical activity than usual care in people with osteoarthritis: a cluster-randomised trial. Journal of Physiotherapy. 2010;56(1):41–7.20500136
27 Friedrich M, Gittler G, Halberstadt Y, . Combined exercise and motivation program: effect on the compliance and level of disability of patients with chronic low back pain: a randomized controlled trial. Archives of Physical Medicine & Rehabilitation. 1998;79(5):475–87.9596385
28 Friedrich M, Gittler G, Arendasy M, . Long-term effect of a combined exercise and motivational program on the level of disability of patients with chronic low back pain. Spine. 2005;30(9):995–1000.15864148
29 Jordan K, Dunn KM, Lewis M, . A minimal clinically important difference was derived for the Roland-Morris Disability Questionnaire for low back pain. Journal of Clinical Epidemiology. 2006;59(1):45–52.16360560
30 Prochaska JO, DiClemente CC. Stages and processes of self-change of smoking: toward an integrative model of change. J Consult Clin Psychol. 1983;51(3):390–5.6863699
31 Ryan RM, Deci EL. Self-determination theory and the facilitation of intrinsic motivation, social development, and well-being. Am Psychol. 2000;55(1):68–78.11392867
32 Michie S, van Stralen MM, West R. The behaviour change wheel: a new method for characterising and designing behaviour change interventions. Implement Sci. 2011;6:42.21513547
33 Bandura A. Social cognitive theory of self-regulation. Organizational Behavior and Human Decision Processes. 1991;50(2):248–287.
34 Gale J, Skouteris H. Health coaching: facilitating health behaviour change for chronic condition prevention and self-management. In: Caltabiano M, Ricciardelli L, eds. Handbook of applied topics in health psychology. Hoboken, NJ: Wiley-Blackwell; 2013.
35 Weinstein ND. The precaution adoption process. Health Psychology. 1988;7(4):355–386.3049068
36 Prochaska JO, DiClemente CC. Transtheoretical therapy: Toward a more integrative model of change. Psychother Theory Res Pract. 1982;19:279–288.
37 Voils CI, Olsen MK, Gierisch JM, . Maintenance of Weight Loss After Initiation of Nutrition Training: A Randomized Trial. Annals of Internal Medicine. 2017(1539-3704 (Electronic)).
38 Voils CI, Gierisch JM, Olsen MK, . Study design and protocol for a theory-based behavioral intervention focusing on maintenance of weight loss: the Maintenance After Initiation of Nutrition TrAINing (MAINTAIN) study. Contemp Clin Trials. 2014(1559-2030 (Electronic)).
39 Kwasnicka D, Dombrowski SU, White M, . Theoretical explanations for maintenance of behaviour change: a systematic review of behaviour theories. Health Psychol Rev. 2016(1743-7202 (Electronic)).
40 Greaves C, Poltawski L, Garside R, . Understanding the challenge of weight loss maintenance: a systematic review and synthesis of qualitative research on weight loss maintenance. Health Psychol Rev. 2017(1743-7202 (Electronic)).
41 Howlett N, Trivedi D, Troop NA, . Are physical activity interventions for healthy inactive adults effective in promoting behavior change and maintenance, and which behavior change techniques are effective? A systematic review and meta-analysis. Translational Behavioral Medicine. 2019(1613-9860 (Electronic)).
42 Tang MY, Smith DM, Mc Sharry J, . Behavior Change Techniques Associated With Changes in Postintervention and Maintained Changes in Self-Efficacy For Physical Activity: A Systematic Review With Meta-analysis. Ann Behav Med. 2019(1532-4796 (Electronic)).
43 French DP, Olander EK, Chisholm A, . Which Behaviour Change Techniques Are Most Effective at Increasing Older Adults’ Self-Efficacy and Physical Activity Behaviour? A Systematic Review. Annals of Behavioral Medicine. 2014;48(2):225–234.24648017
44 Nicolson PJA, Bennell KL, Dobson FL, . Interventions to increase adherence to therapeutic exercise in older adults with low back pain and/or hip/knee osteoarthritis: a systematic review and meta-analysis. British Journal of Sports Medicine. 2017;51(10):791–799.28087567
45 Eisele A, Schagg D, Kramer LV, . Behaviour change techniques applied in interventions to enhance physical activity adherence in patients with chronic musculoskeletal conditions: A systematic review and meta-analysis. Patient Educ Couns. 2019;102(1):25–36.30279029
46 Willett M, Duda J, Fenton S, . Effectiveness of behaviour change techniques in physiotherapy interventions to promote physical activity adherence in lower limb osteoarthritis patients: A systematic review. PLoS One. 2019;14(7):e0219482.31291326
47 American Physical Therapy Association. APTA Guide to Physical Therapist Practice Alexandria, VA: APTA; 2021.
48 Rothman AJ. Toward a theory-based analysis of behavioral maintenance. Health Psychol. 2000;19(1S):64–9.10709949
49 Rothman AJ, Sheeran P, Wood W. Reflective and automatic processes in the initiation and maintenance of dietary change. Ann Behav Med. 2009;38 Suppl 1:S4–17.19787308
50 Schwarzer R, Schuz B, Ziegelmann JP, . Adoption and maintenance of four health behaviors: theory-guided longitudinal studies on dental flossing, seat belt use, dietary behavior, and physical activity. Ann Behav Med. 2007;33(2):156–66.17447868
51 Morey MC, Pieper CF, Crowley GM, . Exercise adherence and 10-year mortality in chronically ill older adults. J Am Geriatr Soc. 2002;50(12):1929–33.12473002
52 US Department of Veterans Affairs. Sharing Whole Health: Peer-to-Peer. 2021.
53 Minns Lowe CJ, Wilson MS, Sackley CM, . Blind outcome assessment: the development and use of procedures to maintain and describe blinding in a pragmatic physiotherapy rehabilitation trial. Clinical Rehabilitation. 2011;25(3):264–74.20971749
54 Azevedo KJ, Ramirez JC, Kumar A, . Rethinking Violence Prevention in Rural and Underserved Communities: How Veteran Peer Support Groups Help Participants Deal with Sequelae from Violent Traumatic Experiences. The Journal of Rural Health. 2020;36(2):266–273.30875145
55 Goldstein KM, Zullig LL, Oddone EZ, . Understanding women veterans’ preferences for peer support interventions to promote heart healthy behaviors: A qualitative study. Preventive medicine reports. 2018;10:353–358.29868391
56 Matthias MS, Kukla M, McGuire AB, . How Do Patients with Chronic Pain Benefit from a Peer-Supported Pain Self-Management Intervention? A Qualitative Investigation. Pain Medicine. 2016;17(12):2247–2255.28025359
57 Chinman M, Henze K, P S. Peer Specialist Toolkit: Implementing Peer Support Services in VHA Pittsburgh, PA: VA Pittsburgh Healthcare System; 2013.
58 US Department of Veterans Affairs. VA Caregiver Support Program: Peer Support Mentoring Program. 2022.
59 Karfopoulou E, Anastasiou CA, Avgeraki E, . The role of social support in weight loss maintenance: results from the MedWeight study. J Behav Med. 2016;39(3):511–8.26801339
60 Schwarzer R, Leppin A. Social Support and Health: A Theoretical and Empirical Overview. Journal of Social and Personal Relationships. 1991;8(1):99–127.
61 Collins LM, Murphy SA, Strecher V. The multiphase optimization strategy (MOST) and the sequential multiple assignment randomized trial (SMART): new methods for more potent eHealth interventions. Am J Prev Med. 2007;32(5 Suppl):S112–8.17466815
62 Hay E, Dziedzic K, Foster N, . 2018.