# ACKNOWLEDGMENTS

The authors are grateful to Liz Wing and Stacy Lavin for editorial and citation management support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Timothy Brindle, PhD
  Scientific Program Manager
  RR&D, Musculoskeletal Health & Function

- Stuart Hoffman, PhD
  Scientific Program Manager
  RR&D, Brain Health & Injury

- Karen Siegel, PT, MA
  Deputy Director
  RR&D

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Teresa Damush, PhD, MA
  Senior Investigator
  VA HSR&D Center for Health Information and Communication

- Gregory Hicks PT, PHD, FAPTA, FGSA
  Professor
  Associate VP for Clinical & Translational Research, UDPI & Director, Clinical Translational ACCEL Program, University of Delaware

- Kathryn Ross, PhD MPH
  Associate Professor
  Department of Clinical and Health Psychology College of Public Health and Health Professions, University of Florida

- Debra Weiner, MD
  Associate Professor of Medicine
  Psychiatry and Anesthesiology in the Division of Geriatrics, University of Pittsburgh School of Medicine

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix E for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential non-financial conflicts of interest identified.