# DISCUSSION

We evaluated the impact of physical rehabilitation programs supplemented with 1 or more adjunct components designed to promote long-term adherence to recommended rehabilitation programs. Specifically, we evaluated the effect of these interventions on self-efficacy for exercise, adherence to recommended home rehabilitation program, and function at ≥ 3 months after completing the index rehabilitation program among adults with hip/knee OA or LBP. Our review is novel; we focus on sustained adherence to physical rehabilitation programs supplemented with adherence-enhancing adjunct components, and we conducted a rigorous analysis of the adjunct components using an established tool, the Behavior Change Technique Taxonomy (v1).^10^

## SUMMARY OF FINDINGS

We identified 10 studies that included physical rehabilitation programs supplemented by adherence-enhancing adjunct interventions. Six studies were theory informed and included elements of the Transtheoretical Model,^30^ Self-Determination Theory,^31^ COM-B (capability, opportunity, and motivation),^32^ Social Cognitive Theory,^33^ and/or Health Change methodology.^34^ None explicitly included Veterans or focused on a predominantly Veteran population. We identified behavior change techniques present in adherence-enhancing adjunct interventions and in control interventions. We found limited evidence of benefit across the included interventions on long-term adherence and no evidence for benefit to functional outcomes, though few of the evaluated adherence interventions were theory based or addressed long-term home rehabilitation program adherence as distinct from initiation. Self-efficacy and adverse events were sparsely reported.

The majority of included studies (60%) delivered the adjunct adherence-enhancing intervention concurrently with the index rehabilitation program. Yet, delivering these approaches at the same time may not be an optimal strategy to foster sustained adherence to PT over time. Moreover, some health behavior models suggest that initiation of PT and long-term adherence to PT are conceptually different behaviors that require different skills and psychological processes for support.^35,36^ If long-term behavioral maintenance of a home rehabilitation program is the appropriate clinical goal for patients with chronic musculoskeletal conditions, then the conceptual difference between starting and sustaining physical rehabilitation is critical. Designing interventions that disentangle behavioral initiation and maintenance (ie, sequential interventions) and target distinct content to support these behaviors may lead to improved results.^7,37–41^

We coded BCTs in adjunct adherence-enhancing interventions and comparator interventions. Comparator interventions generally used BCTs in similar amounts and clusters across studies, which is reflective of typical practice in rehabilitation settings during the initiation of a new home rehabilitation program. Most adjunct adherence-enhancing interventions included few individual BCTs (mean = 5.5), while only 3 included more than 8 BCTs, which prior literature has suggested can enhance behavioral maintenance.^5^ Further, many BCT clusters remain largely unexplored. Because behavior change is a complex phenomenon, the lack of complexity in the adjunct interventions as seen by the few BCT clusters explored remains a missed opportunity. Moreover, the majority of interventions from studies in our review included BCTs from clusters already represented in the comparator arm (such as goal setting, feedback and monitoring, and repetition and substitution). While none addressed a rationale for this overlap, only 1 study specifically refers to the BCTs as a part of intervention development. Because initiating a behavior and behavioral maintenance are distinct psychological processes requiring different skills, goals, and processes of change, designing interventions that focus on “just more of the same” BCTs may be insufficient to promote behavioral maintenance. Studies that were theory informed and embraced the distinction between initiation of behaviors and behavioral maintenance (such as Bennell et al^20^ and Ben-Ami et al^19^) tended to include more BCTs in the adjunct adherence-enhancing interventions and demonstrated BCTs across a broader range of clusters compared to studies that did not address this distinction.

Adherence was generally reported using non-validated self-report measures. Three studies had evidence of a positive effect on our primary outcome of long-term adherence to recommended home rehabilitation programs across end points within included studies. Of these 3 positive studies, 1 was a low-ROB study by Bennell et al^20^ The second study with serious ROB reported a mean difference of 0.7 (95% CI [0.07, 1.3]) on the validated Baecke Physical Activity Questionnaire at 9 months from the end of an enhanced intervention informed by the Transtheoretical Model for patients with LBP. When considering the difference at follow-up between intervention and comparator arms, only the study by Bennell et al^20^ had a beneficial effect for both measures of long-term adherence, specifically general self-reported adherence and adherence as a proportion of the prescribed home rehabilitation program completed, with an SMD of 0.42 (95% CI [0.02, 0.82]) and an SMD of 0.50 (95% CI [0.09, 0.90]), respectively.

All but 1 included study^18^ measured functional outcomes and all used at least 1 established self-report measure of function. Two studies also included objective measures of function including several indicators of strength and flexibility in key lower extremity muscle groups.^21,27^ Three studies with concurrently delivered adherence adjunct interventions reported a positive effect of the intervention on functional status from pre-index rehabilitation to follow-up, but all had some concerns for ROB or were high ROB. To evaluate sustained functional improvement, we considered the difference in change of function from the end of rehabilitation to follow-up. There was no evidence of intervention effect at any time point, including across both concurrently and sequentially delivered interventions and across the 3 low-ROB studies.

We attempted to identify measures of self-efficacy to carry out home practice of prescribed rehabilitation exercise, but given the limited assessments of this construct, we included related constructs (eg, self-efficacy for managing arthritis, motivation to follow [rehabilitation] recommendations, and confidence in doing things [in the context of knee OA]). Of the 5 studies reporting these constructs, only 2 used validated measures specifically related to self-efficacy of any type. One low-ROB study by Bennell et al^20^ used the Arthritis Self-Efficacy Scale and found no difference between the sequentially delivered semi-interactive SMS message adjunct intervention and comparator at 24 weeks across any of the 3 subscales (ie, pain, function, controlling other symptoms). Of the other 4 studies, only 1 high-ROB study^18^ found a significant difference using a non-validated measure assessing confidence-like attitudes. However, we note that self-efficacy is most accurately measured when related to a specific behavior, so these related findings are tangentially relevant. In addition, it is unclear if any of the studies measuring self-efficacy included intervention strategies to specifically target this construct. While we assessed the BCTS of the included interventions, it is unknown which BCTs are most effective at promoting self-efficacy.^42,43^ Four studies reported adverse events, though none found any difference in events by receipt of adjunct adherence interventions and most of those reported were minor musculoskeletal discomforts.

### Certainty of Evidence for Key Outcomes

To contextualize the overall base of the evidence on key outcomes, we conducted Certainty of Evidence (COE) ratings for adherence and function outcomes. These assessments reflect the degree of confidence we have in our summary findings. For each outcome of interest, we present the COE by outcome (ie, adherence, function) and time point (ie, 3 to 6 months, ≥ 9 months). The non-randomized study and studies reporting categorical outcomes are evaluated separately (Table 7).

We identified low COE that adjunct adherence interventions have no effect on adherence to rehabilitation at 3 to 6 months and 9 months after the end of the rehabilitation period. Adjunct components had no significant effect when studies reported adherence as percent adherent to the prescribed dose of rehabilitation. These were also determined to be very low certainty. We found low certainty and very low certainty that adherence interventions have no effect on physical function at 3 to 9 months and very low certainty at 9 months. Ratings of low and very low COE indicate that the true effect of adjunct interventions on long-term adherence to recommended rehabilitation programs and physical function might be considerably different from the estimated effect we found in the included studies. Future studies may shift these COE ratings.

Table 7 Certainty of Evidence for Rehabilitation Adherence by Intervention and Outcome Timing

Intervention | Number of Studies; (N) | Findings | Certainty of Evidence; (Rationale)
Adherence; 3 to 6 months | 4 randomized; (514 participants) | SMD range = 0.05–0.42 (95% CI range = −0.23–0.82) | Very low certainty of no effect; (rated down for serious risk of bias, serious inconsistency, and serious imprecision)
Adherence; 3 to 6 months | 1 randomized; (200 participants) | OR = 2.9 (95% CI [1.2, 6.7]) | Very low certainty of increased adherence; (rated down for serious risk of bias, serious indirectness, and serious imprecision)
Adherence; 9+ months | 2 randomized; (225 participants) | SMD range = −0.12–0.06 (95% CI range = −0.53–0.40) | Very low certainty of no effect; (rated down for serious risk of bias, serious inconsistency, and serious imprecision)
| 1 non-randomized; (189 participants) | SMD = 0.20 (95% CI [−0.09, 0.48]) | Very low certainty of no effect; (rated down for serious risk of bias and serious imprecision)
| 1 randomized; (200 participants) | Adherence to rehabilitation: OR = 3.0 (95% CI [1.5, 6.0]); Adherence to activities: OR = 1.8 (95% CI [0.8, 3.8]) | Very low certainty of increased adherence; (rated down for serious risk of bias, serious indirectness, and serious imprecision)
Adherence % of Dose Prescribed | 4 randomized; (514 participants) | SMD range = −0.03–0.50 (95% CI range = −0.31–0.90) | Very low certainty of no effect; (rated down for serious risk of bias, serious inconsistency, serious imprecision)
Physical Function; 3 to 6 months | 6 randomized; (936 participants) | SMD range = −0.12–0.02 (95% CI range = −0.55–0.24) | Low certainty of no effect; (rated down for serious risk of bias and serious imprecision)
Physical Function; 3 to 6 months | 1 randomized; (200 participants) | OR = 5.3 (95% CI [1.9, 14.8]) | Very low certainty of increased function; (rated down for serious risk of bias, serious indirectness, and serious imprecision)
Physical Function; 9+ months | 4 randomized; (624 participants) | SMD range = −0.23–0.10 (95% CI range = −0.70–0.31) | Low certainty of no effect (rated down for serious risk of bias and serious imprecision)
Physical Function; 9+ months | 1 non-randomized; (189 participants) | Mean = 0.20 (95% CI [−0.09, 0.49]) | Very low certainty of no effect; (rated down for serious risk of bias, and serious imprecision)
Physical Function; 9+ months | 1 randomized; (200 participants) | OR = 2.9 (95% CI [1.2, 6.7]) | Very low certainty of increased function; (rated down for serious risk of bias, serious indirectness, and serious imprecision)

Notes. Randomized and non-randomized designs were not combined as per GRADE guidance.^17^ Studies reporting dichotomous outcomes were not be combined with studies reporting continuous outcomes.

Abbreviations. OR=odds ratio; SMD=standardized mean difference.

## PRIOR SYSTEMATIC REVIEWS

Several prior systematic reviews provide additional context for our findings. Nicolson et al^44^ aimed to determine the effectiveness of interventions to increase adherence to therapeutic exercise among older adults with LBP and/or hip/knee OA. Four studies in this review reported improved adherence from 4 weeks to 12 months (SMD= 0.26–1.23) and standardized mean differences with low to very low COE indicated a small effect in favor of adjunct sessions. Yet, the authors of this review defined adherence in a way that included short-term (< 3 months) adherence or adherence during delivery of a rehabilitation intervention. In contrast, our review focused on adherence following an index rehabilitation intervention and was interested in long-term adherence (≥ 3 months) after completing the index rehabilitation intervention, and few interventions demonstrated improvements in this outcome. Moreover, we allowed the inclusion of high-quality non-randomized trials in our review that were excluded by Nicolson et al. Four^18,23,26,27^ of our included studies overlapped with Nicolson et al, likely due to similar populations, outcomes, and inclusion criteria.^18,23,26,27^ However, our results extend the work of Nicolson et al in providing data on long-term adherence to home rehabilitation programs.

Two prior reviews examined the use of BCTs to improve adherence to exercise or physical activity. Eisele et al^45^ examined the effectiveness of BCTs to enhance physical activity among patients with chronic musculoskeletal conditions across 22 studies (3 included in our review^18,19,25^). A subgroup analysis examining the difference between high BCT (defined as an adherence-enhancing intervention containing ≥ 8 BCTs) and low BCT (defined as an adherence-enhancing intervention containing < 8 BCTs) interventions found a higher effect (SMD = 0.29, 95% CI [0.19, 0.40]) for interventions using a greater number of BCTs. Our results largely follow this trend with the exception of Pisters et al^26^ (adherence-enhancing intervention containing 2 BCTs and a positive effect) and Friedrich et al^27^ (adherence-enhancing intervention containing 10 BCTs and a null result). Comparing our review to Eisele et al reveals that while researchers and clinicians often focus primarily on intervention content, our results point to the importance of considering the comparator arm content in comparison to the intervention. Specifically, we found that adjunct adherence interventions largely employed similar BCTs to those used in comparator arms. To move the field forward, interventions designed to improve long-term adherence to home rehabilitation programs should make sure that intervention BCTs build on and complement those BCTs used in the routine rehabilitation programs that focus on initiating a home rehabilitation program; in particular, interventions should employ BCTs with the theoretical grounding and an evidence base that supports the maintenance of behavior change.

Including 24 studies (2 included in our review),^23,25^ a systematic review by Willett et al^46^ identified 5 BCTs that had high effectiveness ratios (≥ 50%) in promoting adherence to exercise among those with hip/knee OA (behavioral contract, nonspecific reward, goal setting [behavior], self-monitoring of behavior, and social support [unspecified]). Two of the 5 effective BCTs identified by Willett et al were present in nearly all (80%, self-monitoring of behavior) or all (goal setting [behavior]) interventions included in our review. In contrast, 3 of the 5 effective BCTs were rarely seen (behavioral contract, 20%; nonspecific reward, 30%; social support [unspecified], 30%) in our review. Including these BCTs known to be effective at promoting exercise adherence may enhance the effectiveness of future interventions designed to enhance adherence, especially as the intention to perform exercises and social support are previously identified predictors of long-term adherence to exercise.^5^

Jordan et al^11^ completed a Cochrane review of 42 RCTs (1 included in our review^27^) examining interventions including self-management interventions, psychological interventions, and rehabilitation interventions to improve exercise adherence for individuals with chronic musculoskeletal pain. The authors’ conclusions were limited by a lack of high-quality RCTs with long-term follow-up that explicitly address adherence to exercises and the lack of standard validated measures of exercise adherence. Though these recommendations are now 12 years old, based on our review findings we believe that these conclusions remain valid.

## CLINICAL AND POLICY IMPLICATIONS

As noted, we found little evidence for the benefit of existing adjunct adherence interventions on long-term adherence or functional outcomes. Included studies differed in many core features, including patient population, follow-up length, and study quality, as well as in how they approached the goal of engaging patients with chronic musculoskeletal conditions in the long-term practice of prescribed home rehabilitation programs. The adjunct adherence interventions we identified included a limited number of established strategies (ie, BCTs) known to promote sustained behavior change, used the same strategies as are used for initial rehabilitation treatment, and generally did not draw a distinction between initiation and maintenance of home rehabilitation programs.

These findings and methodological limitations make specific clinical recommendations challenging. Nonetheless, we believe a few key concepts may inform current clinical practice. First, rehabilitation clinicians and primary care providers should consider disentangling support for starting a rehabilitation program and coaching to commit to long-term rehabilitation recommendations. In doing so, rehabilitation clinicians should approach the prescription of home rehabilitation as a behavior change initiation conversation and employ appropriate approaches for initiating a new behavior.

Second, typical rehabilitation practice utilizes a number of strategies (ie, BCTs) as part of the standard of care for LBP and lower limb arthritis^47^ (eg, goal setting, behavioral practice, and information about health consequences). When shifting aims to the promotion and encouragement of long-term sustainment of a home rehabilitation practice after successful initiation, clinicians need to employ a targeted and distinct set of strategies for maintenance.^5,7^ Unfortunately, the field lacks evidence-based or clinical guidelines to draw from to inform which strategies, or BCTs, are most appropriate for the promotion of the sustained practice of prescribed home rehabilitation programs in the context of LBP or hip/knee OA. We can draw from other fields of behavioral maintenance that suggest approaches such as a shift in self-regulatory focus^48,49^ (ie, focus on approaching a favorable endpoint vs avoiding a less favorable alternative state), relapse prevention planning, fostering effective self-monitoring, and shifting social support from the physical therapist to the patient’s social network.^50^ We can also look to existing successful VHA programs that seek to promote long-term behavior change. While not rehabilitation specific, the VA has already invested in some programs to promote the long-term physical function of Veterans, using social support. Two such examples include the nationally disseminated VHA Gerofit program, with demonstrated evidence of improvement in morbidity and mortality^51^ (now being disseminated nationwide), and the Peer-To-Peer Whole Health program.^52^

## LIMITATIONS

It is important to consider our findings within the context of both the limitations of our methodological approach to this systematic review and those of the identified literature meeting our inclusion criteria.

Our methodological approach includes multiple strengths, including following an a priori developed protocol, obtaining guidance for approach and eligibility criteria from an expert panel, using a conceptual model to frame our review, and rigorous categorization of behavioral change techniques reported in the included interventions using an established method. It should be noted that we focused this review on common chronic musculoskeletal conditions that require long-term maintenance for improvement of function; findings may not be relevant to other clinical conditions requiring physical therapy for rehabilitation (eg, post joint replacement, after an acute injury). In addition, there may be other studies that did not explicitly intend to promote long-term adherence or measure adherence at time points 3 months and greater but that could provide useful insight into this topic. Further, half of the included studies did not have an a priori focus on long-term adherence and, as such, were not directly designed to address the key question proposed here about maintenance of physical rehabilitation programs. Our use of the BCT taxonomy also has limitations. Although 2 authors independently coded and reviewed the BCTs present in each study, reporting of control arm and intervention arm components was often insufficient. Thus, we cannot guarantee the completeness and comparability of the coded BCTs.

Finally, we did not attempt to combine studies reporting continuous and dichotomous outcomes; a future synthesis employing methods to do so may arrive at different conclusions.”

### Publication Bias

In the context of this review, which found a small number of included studies, existing statistical methods are not useful to detect publication bias. It is possible that there are existing studies or projects evaluating interventions to promote long-term adherence to physical therapy that were not published in the indexed literature. For example, it is possible that individual clinics or health care systems have developed internal programs to promote long-term rehabilitation adherence that have been evaluated as quality improvement projects but not published in the peer-reviewed literature.

### Study Quality

We were also limited by the quality of identified studies. Common potential sources of bias across the included studies included an inadequate description of intervention delivery, deviations from intended intervention delivery, missing outcome data (especially for longer-term outcome assessment time points), and reliance on self-reported outcomes with the potential for bias.

### Heterogeneity

Potential sources of heterogeneity in effects include the participating patient population, the length of follow-up assessments (which ranged from 3 months to 60 months), measurement of key outcomes (eg, type of instrument used), and the type of interventions themselves. Specifically, 6 of the included studies^18,19,24,25,27,28,53^ reported on adjunct adherence interventions delivered concurrently to the index rehabilitation intervention and 2 focused on training the PT providers in advance of providing direct patient care. On the other hand, 4 studies evaluated the effect of interventions delivered after the completion of index rehabilitation care, effectively extending the contact and support provided to participants. While we categorized studies as delivering the adjunct intervention either concurrently to the index rehab program or sequentially, the identified studies were not always easy to classify. In some cases, this was due to overlap of the adherence adjunct intervention both during the index rehab program and subsequently (eg, Pisters et al^26^ and Quicke et al^22^). In addition, we sought to include studies whose sole comparison was the addition of an adjunct adherence intervention to a standard rehabilitation program (ie, A vs A + B study design). However, in an effort to identify potentially relevant literature, some of the included studies did not feature an index rehabilitation intervention identical to that of the comparator (eg, Quicke et al^22^). This was particularly challenging to clarify in studies that administered the adjunct adherence intervention concurrently with the index rehabilitation program.

### Applicability of Findings to the VA Population

While none of the included studies were conducted in the VA or specifically sought to include Veterans, the identified studies were conducted in settings similar to the VA Health Care System, and it is reasonable to expect they would function similarly. In addition, the participants in the included studies are similar in age and comorbidities to Veterans cared for in the VA.

## FUTURE RESEARCH

To guide our assessment of important gaps in the existing literature, we consider each category in the PICOTS (population, intervention, comparator, outcomes, timing, setting) framework (Table 8). We identify those study design characteristics that we feel would provide the greatest contribution to this body of literature given the current state of the evidence. For each of the gaps described in Table 8, we identified that there is currently insufficient information.

Table 8 Highest Priority Evidence Gaps for Long-term PT Adherence

PICOTS Domain | Evidence Gap/Area for Future Exploration
Population | - Populations including underrepresented racial and ethnic groups; - Younger patients with knee and hip osteoarthritis and lower back pain, as their challenges and needs for incorporating long-term strategies into working-age lifestyles may be different from other age groups
Intervention | - Distinction between interventions promoting the initiation of behavior change versus behavioral maintenance grounded in best theoretical/conceptual approaches; - Adherence-enhancing adjunct interventions that use different BCTs than are typically seen in usual rehabilitation care; - Interventions aimed at both the rehabilitation provider and patient simultaneously; - Virtual and/or asynchronous interventions for flexibility and convenience of long-term patient engagement; - Titrating adherence interventions to individual’s needed level of support; - Use of BCTs known to be effective from related literature for long-term home adherence; - Clearly described and varied dose of the intervention delivered to patients
Comparator | - Well-described usual care/standard rehabilitation programs that clearly demonstrate provision of standards of care and identified behavior change techniques; - Various delivery modalities in order to compare in-person to virtually delivered
Outcomes | - Objective functional outcomes (eg, 6-minute walk test, 30-second sit to stand test); - Validated measures specific to self-efficacy for exercise/physical activity; - Standardized and validated measures of adherence (objective when possible, such as accelerometer data)
Timing | - Longer-term outcomes at least 6 months after completion of index rehabilitation program to facilitate comparison across studies
Setting | - Community-based rehabilitation

### Future Intervention Design Considerations

Initiation of behavior change requires a skill set fundamentally different from that needed to maintain behavior change.^7^ Long-term adherence to home rehabilitation programs prescribed by rehabilitation clinicians should be considered behavioral maintenance and thus requires different BCTs, goals, and skills compared to behavioral initiation. Moreover, the potential for the type, sequence, and number of BCTs to interact dynamically to optimally promote behavioral initiation and maintenance offers new avenues for intervention development.

While we are unable to draw definitive conclusions about the type of interventions most likely to lead to long-term adherence and functional improvement, we can suggest the types of strategies that could be explored in the future, including social support, behavioral contracts, and the use of rewards. Social support is particularly intriguing for VA-based rehabilitation adherence efforts, as social support delivered through peer support has been shown to be broadly accepted and effective within the Veteran population,^54–56^ and peer support specialists are already incorporated into multiple kinds of VA care provision.^57,58^ Further, theoretical and empirical evidence suggests the critical role of positive, structural social support from within the patient’s own social network as a key factor in behavioral maintenance.^7,59,60^

The collected literature shows that the field of behavioral maintenance of home rehabilitation programs is nascent. In addition to methodologically rigorous randomized trials testing adjunct interventions designed to promote behavioral maintenance of prescribed home rehabilitation, more recent innovations in clinical trials design such as SMART or MOST designs could be helpful to move this body of literature forward.^61^ Programs should ensure that the adherence adjunct intervention arm is delivered in addition to an index rehabilitation program identical to that administered to the comparator arm (ie, a true A vs A + B comparison). This is particularly important for concurrently delivered adjunct interventions, from which adjunct components are inherently more difficult to disentangle compared to sequentially delivered adjunct intervention studies. Further, studies should consider a purposefully sequenced combination of intervention approaches (ie, behavior initiation followed by behavioral maintenance).

## CONCLUSIONS

Long-term sustainment of functional improvements gained by short-term rehabilitation programs requires ongoing adherence to recommended home rehabilitation programs well past the end of direct clinical treatment. We found that there is inadequate evidence evaluating rigorously designed adherence-enhancing interventions for the specific promotion of long-term adherence to home rehabilitation programs. As long-term adherence represents a distinct behavioral target (ie, behavioral maintenance), future studies may want to consider testing interventions specifically built to target behavioral maintenance of home rehabilitation programs. Future development of interventions to promote long-term or sustained adherence to prescribed home rehabilitation programs could benefit from use of theoretically informed approaches and successful behavioral maintenance interventions validated in similar conditions. In the meantime, rehabilitation clinicians and referring providers should be aware that long-term commitment to prescribed home rehabilitation programs is necessary to realize ongoing health benefits.