# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process (full list of excluded studies available in Appendix D).

Figure 2 Literature Flowchart

Notes. ^a^ Search results from Medline (2,108), Embase (1,111), and CINAHL (101) were combined.

## LITERATURE OVERVIEW

Our search identified 3,320 potentially relevant articles. After removing duplicates, there were a total of 3,320 articles. After applying inclusion and exclusion criteria to titles and abstracts, 81 articles remained for full-text review. Of these, 11 studies (10 unique) were retained for data abstraction, including 1 non-randomized trial, 2 cluster randomized trials, and 7 randomized controlled trials. None were conducted in the VA. The studies were conducted in the United States (1), Canada (1), Australia (3), Europe (4), and Israel (1) (Table 2).

Table 2 Evidence Profile of Included Studies

Number of studies: 11 studies (10 unique interventions)
Study Designs: Cluster randomized controlled trial (n=2); Individual randomized controlled trial (n=7); non-randomized controlled trial (n=1)
Number of participants: 1,964
Countries: Europe (n=4); Australia (n=3); USA (n=1); Canada (n=1); Israel (n=1)
Patient demographics (median): age = 62 years old; women (63%); White (74%) (6 studies not reported), Black (2.3%) (9 studies not reported)
Conditions: Knee osteoarthritis (n=5); Low back pain (n=3); Hip osteoarthritis (n=1); Knee and Hip osteoarthritis (n=1)
BCT components: Mean number of BCTs per index rehabilitation program = 8.8 (range 5 BCTs to 11 BCTs) and mean number of BCTs per adherence adjunct intervention= 6.2 (range 2 BCTs to 15 BCTs)
Duration of index rehabilitation program: Median duration was 3 months (range 1 month to 12 months)
Duration of adherence adjunct: Median duration was 6 months (range 1 month to 24 months)
Intervention timing: Concurrent (n=6); Sequential (n= 4)
Risk of bias: Low (n=4); Some concerns (n=2); High (n=4)^a^; Serious (n=1)^b^

Notes.

a One study was evaluated as low risk of bias for objectively measured outcomes and high risk of bias for patient reported outcomes.^18^

b ROBINS-I tool was used to evaluate the non-randomized controlled trial.^19^

Abbreviations. BCT=behavior change technique.

## MAIN FINDINGS

### Key Points

- We identified 10 studies evaluating adjunct adherence interventions: 6 delivered concurrently to an index rehabilitation program and 4 delivered sequentially.
- Most studies targeted patients with knee and/or hip OA (7 studies).
- There was often similarity in the behavior change techniques used in intervention and comparator groups, and no studies provided a rationale for this overlap.
- Included studies were generally small and only 5 articulated a specific intent to promote long-term adherence.
- Of the 3 studies that reported a positive effect on long-term adherence, only 1 was a low ROB study.
- Included studies with notable limitations showed no meaningful treatment effect on long-term physical function.

### Intervention Characteristics

Of the 10 unique studies included in this review, 4 featured a sequentially delivered adjunct adherence intervention^20–23^ and 6 were delivered concurrently to the index rehabilitation program^18,19,24–27^ (Figure 3). All but 1 study^18^ included some form of traditional physical therapy as the index rehabilitation program, though they varied in duration (1.5 to 6 months) and type (eg, submaximal graded exercise program, strength training). The number of physical rehabilitation sessions (median = 5, range = 2–156) also varied widely across the included studies. The duration of individual sessions and dose actually delivered to patients (eg, sessions attended) were not regularly reported in these studies. Five studies^18,20,21,24,26^ explicitly focused on improving adherence to rehabilitation or home practice or reported adherence as a primary outcome. Five adjunct interventions^18,20–22,25^ were conducted at least partially remotely (eg, telephone, text message). No studies reported using video for adjunct adherence support. The median duration of the adjunct component was 6 months (range = 1–24 months) and the number of sessions ranged from 2 to 42 with a median of 7 sessions. All but 1 study^18^ reported the profession of the provider delivering the adjunct adherence intervention, and all were physical therapists or similarly trained clinicians. Little detail was provided about the training or experience of interventions. Below, we describe the concurrent and sequential adjunct interventions in more detail.

Figure 3 Timing of Rehabilitation and Adjunct Interventions

Notes. ^a^ Participants in the intervention could receive up to 6 extra coaching telephone sessions after the end of the index rehabilitation program. ^b^ The adjunct components were intentionally different during the same timeframe as the rehabilitation program and determined to be concurrent. ^c^ The majority of the unique adjunct components were delivered after the rehabilitation program was completed.

#### Concurrently Delivered Adjunct Adherence Interventions

Three concurrently delivered adjunct interventions targeted chronic LBP, 2 focused on knee OA alone, and 1 studied hip and/or knee OA.^19,24,27^ All 3 studies focused on the treatment of chronic LBP, included specific provider training, or offered treatment approaches as an integrated component of the index rehabilitation program. Specifically, they provided communication training for physical therapists based on self-determination theory^24^ (a transtheoretical, model-informed rehabilitation counseling intervention^19^) and a motivational program co-delivered with a standard rehabilitation program.^27,28^ Two concurrent interventions for patients with hip or knee OA were aligned with more traditional rehabilitation programs. One provided 6 CBT-informed telephone counseling sessions as a supplement during—and then up to an 6 additional sessions after—a standard progressive individualized home rehabilitation program.^25^ The other provided a behavioral-graded activity intervention with an additional 7 booster sessions beyond the end of the index rehabilitation program.^26^ Finally, 1 knee OA program consisted of a supervised community walking program supplemented by concurrent group sessions focused on goal setting and support provision.^18^

#### Sequentially Delivered Adjunct Adherence Interventions

All 4 sequentially delivered adjunct adherence intervention studies targeted patients with knee OA. Two with the same lead author were developed as add-on studies recruiting participants who had completed prior physical therapy trials;^20,23^ the first provided 2 additional booster physical therapy (PT) sessions over the 24 weeks after index rehabilitation,^23^ and the second provided 24 weeks of automated, semi-interactive text messages after index rehabilitation.^20^

Baker et al^21^ provided monthly motivational adherence counseling calls for 18 months after a run-in period of a strength training rehabilitation program, and Quicke et al provided an adherence toolkit including tools for self-monitoring and follow-up adherence sessions.^22^ See Appendix C for additional intervention details.

### Behavior Change Techniques

We identified BCTs targeting adherence to prescribed physical rehabilitation interventions for each study, including for both the intervention and comparator arms (Appendix F). A total of 38 of the total 93 BCTs from the BCT taxonomy (v1)^10^ were identified across the included studies, representing 14 of the 16 BCT clusters (see Appendix G). The number of BCTs in comparator arms ranged from 5 to 11 (mean = 8.8 BCTs), while intervention groups included 2 to 15 unique BCTs (mean = 6.2). Bennell et al^20^ had the most unique BCTs in the adjunct adherence-enhancing intervention (15), followed by Friedrich et al^27^ (10) (Figure 4). Of note, Bennell et al^20^ was the only included study that specifically mentioned incorporation of BCTs and related theory during intervention development. BCTs commonly included in index rehabilitation programs reflect typical clinical practice (examples include goal setting, instruction on how to perform a behavior, demonstration of the behavior, and behavioral practice/rehearsal). Though 14 of 16 BCT clusters were represented across all 10 included studies, 10 BCT clusters were present in ≤ 3 adjunct adherence-enhancing interventions. Adjuncts that demonstrated improved long-term adherence tended to have more unique BCTs compared to those that did not improve adherence. Adjuncts that were delivered concurrently likewise tended to have fewer BCTs than those that were delivered sequentially. Across all included studies, little detail was available about how BCTs were operationalized within the clinical encounters.

Figure 4 Heatmap of BCTs Identified in Index Rehabilitation Programs and Adjunct Adherence Interventions

Notes. Behavior change techniques (BCTs) were categorized by count in each cluster and are presented in colors ranging from white to blue as shown in the key. BCT domains: 1. Goals and planning, 2. Feedback and monitoring, 3. Social support, 4. Shaping knowledge, 5. Natural consequences, 6. Comparison of behavior, 7. Associations, 8. Repetition and substitution, 9. Comparison of outcomes, 10. Reward and threat, 11. Regulation, 12. Antecedents, 13. Identity, 14. Scheduled consequences, 15. Self-belief, 16. Covert learning.

## KEY OUTCOMES OF INTEREST

Included studies measured outcomes at a variety of time points. In Figure 5, we depict the timing of outcomes by study in relationship to the end of the index rehabilitation program in order to emphasize sustainment of outcome effects. For the rest of the results section, we refer to follow-up time points in this manner unless stated otherwise. Note that the primary study publications did not necessarily label assessment time points in this way. One study^23^ reported standard deviation (SD) as a direct measure of change. For all other studies, we computed SDs of change from after treatment to follow-up assuming correlation of 0.5 between after-treatment SD and follow-up SD. For 2 studies,^19,24^ we used mean change from baseline to after treatment and the baseline mean (and corresponding SDs) to compute after-treatment mean change and SDs (assuming 0.5 correlation between baseline and after-treatment measurements). For 1 study, we assumed the number of participants after 12 months of follow-up was the same as the number of participants reported at the end of treatment, as the exact number was not specified.^22^

Figure 5 Timeline of Outcome Reporting

### Adherence to Prescribed Home Rehabilitation Program

Ten studies reported on long-term adherence outcomes.^18–27^ Adherence to the prescribed home rehabilitation program was measured in multiple ways. Only 2 studies employed validated adherence scales; specifically, Ben-Ami et al used the Baecke PA questionnaire,^19^ and Bennell et al 2020 used the Exercise Adherence Rating Scale.^20^ An additional 6 studies reported adherence using unvalidated numeric rating scales (ranging from 5 to 11 points), though the specific prompt varied (Table 3).^20–25^ Six studies assessed self-reported adherence through variations in percent completion of the prescribed home rehabilitation program or physical activity.^18,20,22–25^ One study reported the proportion of adherent participants per study arm,^26^ and 1 study reported the number of weeks participants reported being adherent after completion of the index rehabilitation program.^27^ Adherence was measured at time points ranging from 3 months to 5 years after completion of the index rehabilitation program. Six studies measured adherence at only 1 relevant time point (ranging from 3 to 24 months after the end of the index rehabilitation program).^18–21,23,24^

Next, we report findings for adherence outcomes across studies that evaluated the effect of concurrent and then sequentially delivered adjunct interventions.

#### Concurrently Delivered Adjunct Adherence Interventions (N = 6)

Six studies evaluated the effect of concurrently delivered adjunct interventions reported on adherence to prescribed home rehabilitation programs.^18,19,24–27^ Overall, there was no evidence of benefit with concurrently delivered adjunct interventions at 3 to 6 months (SMD range = 0.05–0.06) or 9 months and longer (SMD range = 0.06–0.20) among those studies with continuous outcome measures (Figures 6, 7, 8). The 1 low-ROB study by Bennell et al (2017) evaluated the concurrent delivery of 6 telephone-delivered coaching sessions with up to 6 additional sessions delivered after index rehab.^25^ Authors found no significant difference in adherence between intervention and comparator at 6 months post-rehab or 12 months as measured by self-rated adherence by NRS or percent prescribed home exercises completed. Lonsdale et al, the largest (albeit a high ROB) study with 207 participants with chronic LBP, found no effect of communication skills training for physical therapists on adherence at 3 months.^24^ Finally, another serious-ROB study by Ben-Ami et al reported a mean difference of 0.7 (95% CI [0.07, 1.3]) on the validated Baecke Physical Activity Questionnaire (range = 1–5; higher = greater activity level) from baseline (pre-index rehab program) to 12 months post-baseline for patients with chronic LBP who had received a 3-month enhance transtheoretical model intervention versus usual care PT.^19^ However, when the mean difference between arms at 9 months post-index rehabilitation was considered, there was no significant treatment effect (SMD = 0.20, 95% CI [−0.09, 0.48]; Figure 7).

Pisters et al, a study with some concerns for ROB, reported adherence as a dichotomous outcome (ie, being adherent to prescribed rehabilitation or not).^26^ Authors evaluated 18 sessions of a behavioral rehabilitation program followed by 7 booster sessions compared to 18 sessions of usual PT care among 200 patients with hip/knee OA and reported a greater odds of participants being adherent to prescribed rehabilitation in the intervention group compared with usual care at 13 months post-index rehabilitation (OR = 3.0, 95% CI [1.5, 6.0]). The other concurrent studies not included in the forest plot were a high ROB studies.^18,28^ One that reported similar means across study arms for adherence at 3 months, 11 months, and 5 years.^27^ One reported no evidence of significant benefit at 9 months (Table 3).^18^

#### Sequentially Delivered Adjunct Adherence Interventions (N = 4)

Four studies (2 low, 1 some concerns, and 1 high ROB) with sequentially delivered adherence interventions reported adherence outcomes.^20–23^ Overall, one low ROB study reported beneficial effects. Bennell et al, evaluated the effect of 24 weeks of automated, semi-interactive text messages delivered after index rehabilitation on adherence as measured by the validated Exercise Adherence Rating Scale (score range = 0–24; higher = better adherence) among 110 patients with knee OA.^20^ They found higher rates of adherence at 6 months post-index rehabilitation with a mean difference of 3.1 (95% CI [0.8, 5.5]) and a mean difference of 0.6 (95% CI [0.2, 1.0]) additional days that home rehabilitation was completed in the last week. This translated to an SMD of 0.42 (95% CI [0.02, 0.82]). The other low ROB study, Bennell et al (2014), evaluated the sequential delivery of 2 PT booster sessions on 74 participants with knee OA over 24 weeks after index rehabilitation and found no significant effect on adherence (SMD = 0.18, 95% CI [−0.28, 0.63]).^23^

Of the other 2 studies with sequentially delivered interventions, 1 had some concerns for ROB,^22^ and 1 had high ROB.^21^ They reported no evidence of significant benefit at 24 months (Table 3).^21^

Table 3 Adherence to Prescribed Home Rehabilitation Program

Study; Risk of Bias | Time After End of Rehabilitation Program | Outcome
Concurrent
Bennell, 2017^25^; Low ROB | 6 months | Home rehabilitation adherence (percentage of prescribed sessions completed); Intervention mean = 42% (95% CI [34, 50]); Comparator mean = 39% (95% CI [31, 48]); Mean difference = 2% (95% CI [−10%, 14%]); Self-rated home rehabilitation adherence into NRS; Intervention mean = 4.1 (95% CI [3.3, 4.9]); Comparator mean = 3.9 (95% CI [3.1, 4.7]); Mean difference = 0.2 (95% CI [−0.8, 1.3])
Bennell, 2017^25^; Low ROB | 12 months | Home rehabilitation adherence (percentage of prescribed sessions completed); Intervention mean = 39% (95% CI [31, 46]); Comparator mean = 37% (95% CI [28, 46]); Mean difference = 1% (95% CI [−10, 12]); Self-rated home rehabilitation adherence into NRS; Intervention mean = 3.8 (95% CI [3.1, 4.6]); Comparator mean = 3.6 (95% CI [2.9, 4.4]); Mean difference = 0.2 (95% CI [−0.8, 1.2])
Pisters, 2010^26^; Some concerns about ROB | 13 months | Self-rated questionnaire - adherence to rehabilitation; Intervention: 46/79; Comparator: 24/72; OR = 3.0 (95% CI [1.5, 6.0]); Self-rated questionnaire - adherence to activities; Intervention = 32/71; Control = 17/54; OR = 1.8 (95% CI [0.8, 3.8])
Brosseau, 2012^18^; High ROB | 9 months | Number of attended walking sessions/ number of prescribed sessions; Intervention mean = 0.445 (SD = 0.433); Comparator mean = 0.446 (SD = 0.441); Mean difference = NR, p-value = 0.989
Ben-Ami, 2017^19^; Serious ROB | Estimated at 9 months | Baecke Physical Activity Questionnaire (BPAQ); Intervention mean = 0.8 (95% CI [0.4, 1.3]); Comparator mean = 0.1 (95% CI [−0.3, 0.6]); Mean difference = 0.7 (95% CI [0.07, 1.3])
Friedrich, 1998^27^; Companion: Friedrich 2005^28^; High ROB | 3 months | Treatment compliance after termination of the treatment program in weeks; Intervention mean = 10.6 (SD = 2.7); Comparator mean = 10.3 (SD = 2.9); Mean difference = NR
Friedrich, 1998^27^; Companion: Friedrich 2005^28^; High ROB | 11 months | Treatment compliance after termination of the treatment program in weeks; Intervention mean = 28.8 (SD = 18.5); Comparator mean = 30.1 (SD = 20.5); Mean difference = NR
Friedrich, 1998^27^; Companion: Friedrich 2005^28^; High ROB | 5 years | Years that rehabilitation program was performed regularly; Intervention mean = 3.5 (SD = 2.0); Comparator mean = 4.4 (SD = 2.2); Mean difference = NR
Lonsdale, 2017^24^; High ROB | 3 months | Specific adherence to back rehabilitation at home (percentage of prescribed sessions completed per week); Mean difference = 2.57 (95% CI [−6.05, 11.19]); Home based adherence (self-reported overall adherence to their physiotherapists’ recommendations using 7-point rating scales); Mean difference = 0.35 (95% CI [−0.13, 0.83])
Sequential
Bennell, 2014^23^; Low ROB | 6 months | Self-reported adherence to home rehabilitation; Intervention mean = 6.1 (SD = 3.2); Comparator mean = 5.5 (SD = 3.5); Mean difference = 0.6, p-value > 0.05; Home rehabilitation sessions completed; Intervention mean = 56% (SD = 34); Comparator mean = 51% (SD = 37); Mean difference = NR, p-value > 0.05
Bennell, 2020^20^; Low ROB | 6 months | Exercise Adherence Rating Scale (EARS); Intervention mean = 16.3 (SD = 6.6); Comparator mean = 13.4 (SD = 7.1); Mean difference = 3.1 (95% CI [0.8, 5.5]); Number of days home rehabilitation completed in the past week; SMS Intervention mean = 1.9 (SD = 1.2); Comparator mean = 1.3 (SD = 1.2); Mean difference = 0.6 (95% CI [0.2, 1.0])
Quicke, 2017^22^; Some concerns about ROB | 3 months | “Been doing exercises as often as advised” (n (%)); Targeted rehabilitation adherence arm: Strongly agree = 22 (17%); Agree = 72 (57%); Not sure = 14 (11%); Disagree = 17 (13%); Strongly disagree = 2 (2%); Usual care arm: Strongly agree = 15 (11%); Agree = 48 (36%); Not sure = 23 (17%); Disagree = 36 (27%); Strongly disagree = 11 (8%)
Quicke, 2017^22^; Some concerns about ROB | 12 months | “Been doing exercises as often as advised” (n (%)); Targeted rehabilitation adherence arm: Strongly agree = 18 (15%); Agree = 42 (36%); Not sure = 22 (19%); Disagree = 25 (21%); Strongly disagree = 10 (9%); Usual care arm: Strongly agree = 12 (9%); Agree = 50 (37%); Not sure = 17 (13%); Disagree = 42 (31%); Strongly disagree = 13 (10%)
Baker, 2020^21^; High ROB | 24 months | “How would you rate your level of adherence to the prescribed BOOST exercise program over the last 3 months?”; Intervention mean = 3.63 (95% CI [2.70, 4.56]); Control mean = 4.01 (95% CI [3.03, 4.99]); Mean difference = −0.38 (95% CI [−1.67, 0.91])

Abbreviations. NR=not reported; NRS=numeric rating scale; OR=odds ratio; ROB=risk of bias; SD=standard deviation.

Figure 6 Forest Plot of Adherence Outcomes at 3 to 6 Months

Notes. Bennell 2017 outcomes reported at 6 months after end of rehabilitation; Lonsdale 2017 outcomes reported at 3 months after end of rehabilitation; Bennell 2014 outcomes reported at 6 months after end of rehabilitation; Bennell 2020 outcomes reported at 6 months after end of rehabilitation.

Figure 7 Forest Plot of Adherence Outcomes at 9+ Months

Notes. Bennell 2017 outcomes reported at 12 months after end of rehabilitation; Ben-Ami 2017 outcomes reported at approximately 9 months after end of rehabilitation; Baker 2020 outcomes reported at 24 months after end of rehabilitation. ^a^ Computer-based telephone counseling.

Figure 8 Forest Plot of Adherence Outcomes as Percent of Prescribed Rehabiliation

Notes. Lonsdale 2017 outcomes reported at 3 months after end of rehabilitation; Bennell 2014 outcomes reported at 6 months after end of rehabilitation; Bennell 2020 outcomes reported at 6 months after end of rehabilitation. ^a^ Bennell 2017 outcomes reported at 6 months after end of rehabilitation. ^b^ Bennell 2017 outcomes reported at 12 months after end of rehabilitation.

### Physical Function

All but 1^18^ of the 10 included studies reported on function as an outcome to evaluate intervention impact. Across the studies, function was assessed by several established self-reported outcome measures including the Western Ontario and McMaster Universities Osteoarthritis Index (WOMAC)—a well-validated, self-report measure for individuals with OA with a functional status subscale,^21–23,25^ the Roland-Morris Disability Questionnaire for back pain,^19,24^ the Knee and Osteoarthritis Outcome Score (KOOS) functional subscale,^20^ and the low back outcome score.^27^ Two studies reported both self-reported function and objective measures of function including several indicators of strength and flexibility in key lower extremity muscle groups.^21,27^ As noted above for adherence outcomes, function was assessed at a range of time points spanning from 3 months to 5 years from the end of the index rehabilitation program. Functional status was considered the primary outcome or co-primary outcome in 4 studies.^19,22,23,25^

For functional outcomes, we considered the difference in change from end of index to follow-up between study arms. For concurrently delivered adherence adjunct interventions, function was typically reported as baseline (pre-index rehabilitation) to follow-up; thus, we calculated the mean difference in change from end of rehabilitation to follow-up from reported data when possible.

#### Concurrently Delivered Adjunct Adherence Interventions (N = 5)

Among the 5 concurrently delivered adherence adjunct interventions^19,24–27^ that measured function as an outcome, 4 were rated to have high or serious ROB.^19,24,25,27^ Pisters et al^26^ was rated to have some concerns for ROB and reported functional status via the indirect assessment of meeting physical activity recommendations among participants with hip or knee OA who received usual physiotherapy with or without an adjunct intervention informed by operant conditioning and self-regulation principles. They reported a higher proportion of individuals in the intervention arm achieved rehabilitation goals versus the comparator arm at both end of index rehabilitation (OR = 5.3, 95% CI [1.9, 14.8]) and 12 months after end of index rehabilitation (OR = 2.9, 95% CI [1.2, 6.7]). Of the 4 high/serious ROB studies, only 1 reported a positive intervention effect. Ben-Ami et al found a significant intervention benefit for difference in change of functional status as measured by the Roland-Morris Disability Questionnaire from pre-index rehabilitation program to 9 months post-index rehabilitation (change in mean difference = 2.7, 95% CI [0.9, 4.5]).^19^ This falls below the estimated clinically meaningful difference of 3–5-point threshold.^29^ Finally, 2 papers from Friedrich et al report on a single high ROB study that examined the addition of a motivational counseling intervention to a submaximal graded rehabilitation program and found better performance on the fingertip-to-floor distance test at 3 months after the end of intervention in the motivation adjunct group that was not sustained at 11 months.^27,28^ See Table 4 for additional details. However, when considering mean change from end of index rehabilitation to follow-up as measured by SMD, there was no evidence of benefit among concurrently delivered adjunct interventions at 3–6 months (SMD range = −0.12– −0.02). At 9 months or longer, SMDs were generally larger, but were more inconsistent than at earlier timepoints and were nonsignificant (SMD range = −0.23–0.20) (Figures 9 and 10).

#### Sequentially Delivered Adjunct Adherence Interventions (N = 4)

Four studies delivered adjunct adherence interventions after the end of the index rehabilitation program and also measured functional outcomes.^20–23^ By design, sequentially delivered trials evaluated effect as a mean difference from intervention baseline (ie, end of index rehabilitation) to follow-up time point. There was no evidence of significant treatment effect at 3 to 6 months (SMD range = −0.04–0.02) across 2 low ROB studies and one with some concerns (Figure 9). Similarly, there was no evidence of significant treatment effect at 9 months or longer (SMDs = −0.04 and 0.10) in 1 high ROB study and 1 study with some concerns for ROB (Figure 10). Of note, there was no evidence of intervention effect on function at 6 months for the 1 low ROB study by Bennell et al that demonstrated improved adherence among participants receiving 24 weeks of sequentially delivered behavior change text messages.^20^

Table 4 Physical Function Results

Study; Risk of Bias | Time After End of Rehabilitation Program | Outcome
Concurrent
Bennell, 2017^25^; Low ROB | 6 months | Western Ontario and McMaster Universities Osteoarthritis Index (function subscale); Intervention mean at end of rehabilitation = 52.6 (SD = 16.3); Comparator mean at the end of rehabilitation = 48.8 (SD = 16.4); Intervention mean = 13.3 (SD = 10.5); Comparator mean = 17.4 (SD = 11.9); Mean difference = 3.9 (95% CI [−0.3, 8.2])^a^; SMD (change from end of treatment) = −0.05 (95% CI [0.39, 0.28])
Bennell, 2017^25^; Low ROB | 12 months | Western Ontario and McMaster Universities Osteoarthritis Index (function subscale); Intervention mean at end of rehabilitation = 52.6 (SD = 16.3); Comparator mean at the end of rehabilitation = 48.8 (SD = 16.4); Intervention mean = 12.2 (SD = 10.5); Comparator mean = 16.4 (SD = 11.7); Mean difference = 3.9 (95% CI [−1.0, 8.7])^a^; SMD (change from end of treatment) = −0.06 (95% CI [−0.41, 0.28])
Pisters, 2010^26^; Some concerns about ROB | 13 months | Meeting recommendations for physical activity; Intervention = 76/87; Comparator = 67/92; OR = 2.9 (95% CI [1.2 to 6.7])
Ben-Ami, 2017^19^; Serious ROB | Estimated at 9 months | Roland-Morris Disability Questionnaire; Intervention change in mean from baseline = 6.7 (95% CI [5.4, 8.0]); Comparator change in mean from baseline = 4.0 (95% CI [2.7 to 5.2]); Change in mean difference = 2.7 (95% CI [0.9, 4.5]); SMD (change from end of treatment) = 0.20 (95% CI [−0.09, 0.49])
Friedrich, 1998^27^; Companion: Friedrich 2005^28^; High ROB | 3 months | Low back outcome score; Intervention mean = 57.2 (SD = 15.7); Comparator mean = 51.0 (SD = 15.7); Mean difference = NR; Fingertip to floor distance; Intervention mean = 8.6 (SD = 18.6); Comparator mean = 16.6 (SD = 18.4); Mean difference = NR, p-value = 0.01; SMD (change from end of treatment) = −0.12 (95% CI [−0.55, 0.30])
Friedrich, 1998^27^; Companion: Friedrich 2005^28^; High ROB | 11 months | Fingertip to floor distance; Intervention mean = 4.3 (SD = 6.1); Comparator mean = 10.1 (SD = 13.0); Mean difference = NR, p-value = 0.052; Low back outcome score; Intervention mean = 58.9 (SD = 12.6); Comparator mean = 50.9 (SD = 18.7); Mean difference = NR; SMD (change from end of treatment) = −0.23 (95% CI [−0.70, 0.24])
Friedrich, 1998^27^; Companion: Friedrich 2005^28^; High ROB | 5 years | Disability; Intervention mean = NR; Comparator mean = NR; Mean difference = NR; Intervention arm showed greater improvement in disability vs control between 12 months and 5 years (p-value = 0.003)
Lonsdale 2017^24^; High ROB | 3 months | Roland-Morris Disability Questionnaire; Intervention mean = NR; Comparator mean = NR; Difference in change from baseline intervention vs Comparator = 0.09 (95% CI [−1.43, 1.6]); SMD (change from end of treatment) = −0.02 (95% CI [−0.29, 0.25])
Sequential
Bennell, 2014^23^; Sequential; Low ROB | 6 months | Western Ontario McMaster Universities Osteoarthritis Index (function subscale); Intervention mean = 20.2 (SD = 12.4); Comparator mean = 21 (SD = 12.3); Mean difference = −0.3 (95% CI [−0.4, 3.5])^b^; SMD (change from end of treatment) = −0.02 (95% CI [−0.48, 0.43])
Bennell, 2020^20^; Sequential; Low ROB | 6 months | Function Knee Injury and Osteoarthritis Outcome Score (KOOS) function subscale; Intervention mean = 72.4 (SD = 17.6); Comparator mean = 70 (SD = 21.1); Mean difference = −0.2 (95% CI [−6.7, 6.3])^b^; SMD (change from end of treatment) = −0.04 (95% CI [−0.44, 0.36])
Quicke, 2020^22^; Sequential; Some concerns about ROB | 3 months | Western Ontario McMaster Universities Osteoarthritis Index (function subscale); Intervention mean = 22.7 (SD = 13.3); Comparator mean = 22.3 (SD = 13.3); Mean difference = −0.7 (95% CI [−3.3, 1.9])^a^; SMD (change from end of treatment) = 0.02 (95% CI [−0.19, 0.24])
Quicke, 2020^22^; Sequential; Some concerns about ROB | 12 months | Western Ontario McMaster Universities Osteoarthritis Index (function subscale); Intervention mean = 23 (SD = 14.4); Comparator mean = 21.5 (SD = 14.4); Mean difference = 0.4 (95% CI [−2.6, 3.3])^a^; SMD (change from end of treatment): 0.10 (95% CI [−0.11, 0.31])
Baker, 2020^21^; Sequential; High ROB | 24 months | Western Ontario McMaster Universities Osteoarthritis; Index function subscale; Intervention mean = 12.74 (95% CI [9.78, 15.69]); Comparator mean = 13.09 (95% CI [9.76, 16.43]); Mean difference = −0.46 (95% CI [−4.84, 3.93])^b^; SMD (change from end of treatment) = −0.04 (95% CI [−0.46, 0.37]); Quad strength; Intervention mean = 0.30 (95% CI [0.27, 0.34]); Comparator mean = 0.32 (95% CI [0.28, 0.35]); Mean difference = 0.02 (95% CI [−0.01, 0.05]); Hamstring strength; Intervention mean = 0.15 (95% CI [0.13, 0.17]); Comparator mean = 0.16 (95% CI [0.14, 0.18]); Mean difference = 0.00 (95% CI [−0.02, 0.02]); Timed up and go test (seconds); Intervention mean = 7.45 (95% CI [6.91, 8.00]); Comparator mean = 7.71 (95% CI [6.71, 8.71]); Mean difference = −0.19 (95% CI [−1.13, 0.75]); Repeated chair stands (5 times, seconds); Intervention mean = 13.43 (95% CI [12.40, 14.45]); Comparator mean = 13.40 (95% CI [12.50, 14.31]); Mean difference = −0.12 (95% CI [−1.55, 1.31]); Stair climb (seconds); Intervention mean = 13.72 (95% CI [12.14, 15.30]); Comparator mean = 13.53 (95% CI [11.11, 15.94]); Mean difference = 0.31 (95% CI [−1.81, 2.43])

Notes.

a Change from pre-rehabilitation baseline to follow-up.

b Change from post-rehabilitation baseline to follow-up.

Abbreviations. NR=not reported; NRS=numeric rating scale; OR=odds ratio; ROB=risk of bias; SD=standard deviation; SMD=standardized mean difference.

Figure 9 Forest Plot of Physical Function Outcomes at 3 to 6 Months

Notes. Bennell 2017 outcomes reported at 6 months after end of rehabilitation; Friedrich 1998 outcomes reported at 3 months after end of rehabilitation; Lonsdale 2017 outcomes reported at 3 months after end of rehabilitation; Bennell 2014 outcomes reported at 6 months after end of rehabilitation; Bennell 2020 outcomes reported at 6 months after end of rehabilitation; Quicke 2017 outcomes reported at 3 months after end of rehabilitation.

Figure 10 Forest Plot of Physical Function Outcomes at 9 Months

Notes. Bennell 2017 outcomes reported at 12 months after end of rehabilitation; Friedrich 1998 outcomes reported at 11 months after end of rehabilitation; Ben-Ami 2017 outcomes reported approximately 9 months after end of rehabilitation; Quicke 2017 outcomes reported at 12 months after end of rehabilitation; Baker 2020 outcomes reported at 24 months after end of rehabilitation. ^a^ Computer-based telephone counseling.

### Self-Efficacy

Five studies reported on self-efficacy for exercise or related constructs as an intermediate outcome of interest due to its role as an important determinant of long-term adherence. Two of the 4 studies measuring self-efficacy were delivered concurrently^18,24^ and 2 were delivered sequentially.^20,22^ One additional study with a concurrent intervention^27^ reported on motivation, a distinct but related construct that, for the purpose of this review, is reported here. In all 5 studies, self-efficacy was reported as a secondary outcome (Table 5).

#### Concurrently Delivered Adjunct Adherence Interventions (N = 3)

All 3 concurrent studies reporting self-efficacy-related constructs had high ROB. The Lonsdale^24^ study examined 2 subdomains: “autonomous motivation to follow recommendations” (subdomain of the Treatment Self-Regulation Questionnaire) and “controlled motivation to follow recommendations” (subdomain of the Treatment Self-Regulation Questionnaire) among patients with chronic LBP and found no significant intervention effect. The Friedrich^27^ study reported motivation towards exercise therapy via selected questions from a Psychotherapy Motivation Questionnaire and found no significant difference.

The third concurrent^18^ study examined the “confidence about doing things” and “coping with symptoms” subdomains of the Stanford Questionnaire on Chronic Disease among patients with knee OA and reported a significantly improved “confidence about doing things” at 6 months post-index rehabilitation in the intervention group (a behavioral adjunct intervention delivered concurrently to a supervised walking intervention) versus walking intervention alone (p = 0.041).

#### Sequentially Delivered Adjunct Adherence Interventions (N = 2)

Both sequential studies (1 with some concerns for ROB^22^ and 1 low ROB^20^) utilized validated measures for self-efficacy: Self-Efficacy for Exercise Scale (SEE), which they used to measure a participant’s “confidence in ability to exercise,”^22^ and the Arthritis Self-Efficacy Scale (ASES), which breaks down self-efficacy as it relates to “pain,” “function,” and “other.”^20^ Bennell et al (2020) found no evidence of treatment effect on any of the subdomains at 24 weeks after index rehab program. Quicke et al^22^ reported no statistically significant change within or between treatment arms.

Table 5 Self-efficacy Results

Study; Risk of Bias | Time After End of Rehabilitation Program | Outcome
Concurrent
Brosseau, 2012^18^; High ROB | 6 months | Stanford questionnaire on chronic disease; coping with symptoms subdomain; Intervention mean = 1.388 (SD = 0.856); Comparator mean = 1.064 (SD = 0.952); p-value = 0.286
Brosseau, 2012^18^; High ROB | 6 months | Stanford questionnaire on chronic disease; confidence about doing things subdomain; Intervention mean = 7.546 (SD = 1.848); Comparator mean = 7.690 (SD = 1.920); p-value = 0.041
Friedrich, 1998^27^; Companion: Friedrich 2005^28^; High ROB | Estimated at 9 months | Attitude towards exercise therapy; Intervention mean = 6.3 (SD = 1.6); Comparator mean = 5.6 (SD = 2.1)
Lonsdale 2017^24^; High ROB | 3 months | Autonomous motivation to follow recommendations; Mean difference = −0.10 (95% CI [−0.35, 0.16]), p-value = 0.41
Lonsdale 2017^24^; High ROB | 3 months | Controlled motivation to follow recommendations; Mean difference = −0.15 (95% CI [−0.69, 0.38]), p-value = 0.57
Sequential
Bennell, 2020^20^; Sequential; Low ROB | 6 months | Arthritis Self-Efficacy Scale (ASES); Self-efficacy: pain; Intervention mean = 6.6 (SD = 2.2); Comparator mean = 6.4 (SD = 2.1); Difference in change from baseline between groups = −0.4 (95% [CI −1.2, 0.4]); Self-efficacy: function; Intervention mean = 8.3 (SD = 1.5); Comparator mean = 8.2 (SD = 1.7); Difference in change from baseline between groups = 0.1 (95% CI [−0.5, 0.7])
Quicke, 2020^22^; Sequential; Some concerns about ROB | 3 months | Self-Efficacy for Exercise (SEE); Intervention mean = 5.7 (SD = 2.2); Comparator mean = 5.4 (SD = 2.3); Mean difference = 0.4 (95% CI [0.8, −0.2])

Abbreviations. ROB=risk of bias; SD=standard deviation.

### Adverse Events

Four studies reported adverse events associated with interventions to improve long-term adherence to rehabilitation programs^20,22,23,25^ Overall, there was no evidence of increased adverse events among patients receiving adjunct adherence interventions (Table 6).

Bennell et al (2014)^23^ determined adverse events by questionnaire at the end of a 24-week adjunct intervention of 2 booster PT sessions after an index rehabilitation program. They reported few adverse events; specifically, 6 participants reported increased knee pain (4 intervention vs 2 control) and 1 participant from the control group reported increased hip pain.

A second study by Bennell et al (2017)^25^ collected adverse event reports prospectively through log sheets collected every 3 months for an adjunct telephone coaching intervention delivered concurrently to an index rehabilitation program. They reported that adverse events occurred primarily during intervention delivery and were infrequent during the post-treatment follow-up period. During the treatment phase, 21 of 84 participants from the intervention arm reported 23 adverse events, compared with 21 of 84 participants in the comparator arm reporting 27 adverse events. The most common event was increased knee pain (17 or 26% intervention vs 16 or 23% comparator). Other adverse events were reported less frequently, including pain in other regions, swelling/inflammation, and increased stiffness. Adverse events were less frequent during the follow-up period from the end of the index intervention to 12 months post-end of index, when 7 intervention participants reported 8 adverse events and 12 comparator participants reported 13 events. Similarly, increased knee pain was most frequent.

A third study by Bennell et al (2020)^20^ considered adverse events to be “any problem participant believed was caused by advice received and required them to seek treatment or take medication and/or interfered with function for ≥ 2 days.” They found no difference in overall adverse events between arms (16% sequentially delivered behavioral change text message intervention vs 15% usual care, p = 0.53), for knee pain (9% vs 6%, p = 0.38), or pain in other areas (7% vs 9%, p = 0.48).

Quicke et al^22^ reported 2 adverse events in the arms of interest for this review; 1 participant in the comparator arm had a twisted ankle, and 1 in the sequential monitoring intervention arm had a fall while walking. Of note, the authors reported expected soreness and transient increases in pain among 12% of intervention participants and 19% of comparator participants.

Table 6 Adverse Events Results

Study; Risk of Bias | Time After End of Rehabilitation Program | Outcome
Concurrent
Bennell, 2017^25^; Low ROB | 12 months | Number of adverse events during treatment phase; Total number:; Intervention = 7 (11%); Comparator = 2 (19%); Increased knee pain:; Intervention = 5 (8%); Comparator = 9 (15%); Pain in other region:; Intervention = 2 (3%); Comparator = 4 (6%); Swelling/Inflammation:; Intervention = 1 (2%); Comparator = 0 (0%)
Sequential
Bennell, 2014^23^; Low ROB | 6 months | Adverse events; Increased knee pain:; Intervention = 4; Comparator = 2; Increased hip pain:; Intervention = 0; Comparator = 1
Bennell, 2020^20^; Sequential; Low ROB | 6 months | Any adverse event; Intervention = 9 (16%); Comparator = 8 (15%); p-value = 0.53; Knee pain:; Intervention = 5 (9%); Comparator = 3 (6%); p-value = 0.38; Pain in other areas:; Intervention = 4 (7%); Comparator = 5 (9%); p-value = 0.48
Quicke, 2020^22^; Sequential; Some concerns about ROB | 12 months | Adverse events; Sprained ankle:; Intervention = 0; Comparator = 1; Fall while walking:; Intervention = 1; Comparator = 0

Abbreviations. ROB=risk of bias.

### Quality of Evidence

Risk of bias was assessed separately for each study design and outcome type (ie, patient reported and objectively measured) using the RoB 2 and the ROBINS-I tools. Overall, only 4 studies were judged to be low ROB. Key sources of bias across study designs and outcomes include deviations from intended intervention, bias in outcome assessment, and missing outcome data. Missing outcome data was a particular issue for studies reporting outcomes at later time points. Four studies were downgraded to high ROB on the missing outcome data domain.^18,21,24,27^

For the 7 individually randomized controlled trials, the ROB (Figure 11) for patient-reported outcomes was judged to be low for 3 studies, some concerns for 1 study, and high for 3 studies.^18,20–23,25,27^ Patterns that led to judgments of high ROB and some concerns for ROB (Figure 12) included (1) some concerns about the randomization process; (2) deviations from intended interventions; (3) deviations from adherence to the intervention; (4) missing outcome data; (5) bias in measurements of the outcome; and (6) bias in selection of the reported result.

Of the 3 individually randomized controlled trials reporting objective outcomes, 1 was low risk and 2 were high risk.^18,21,27^ Patterns that led to judgments of high ROB (Figure 13 and 14) included: (1) some concerns about the randomization process; (2) deviations from intended interventions; (3) some concerns about deviations from adherence to the intervention; (4) missing outcome data; (5) bias in measurements of the outcome; and (6) bias in selection of the reported result.

Of the 2 cluster-randomized controlled trials, 1 was judged to have some concerns and 1 was judged as high ROB.^24,26^ Patterns that led to judgments of high ROB and some concerns for ROB (Figure 15 and 16) included: (1) missing outcome data; (2) bias in measurements of the outcome; and (3) some concerns for bias in selection of the reported result.

The 1 non-randomized study evaluated with the ROBINS-I tool was assessed to have serious risk of bias.^19^ Patterns that led to judgments of high ROB and some concerns for ROB included: (1) bias due to confounding; (2) bias due to deviations from intended interventions; (3) moderate risk of bias due to measurement of outcomes; and (4) bias in selection of reported results (Figure 17).

Figure 11 Risk of Bias Ratings Across Randomized Trials: Patient-reported Outcomes

Figure 12 Risk of Bias Ratings by Bias Domain: Patient-reported Outcomes

Figure 13 Risk of Bias Ratings Across Randomized Trials: Objective Outcomes

Figure 14 Risk of Bias Ratings by Bias Domain: Objective Outcomes

Figure 15 Risk of Bias Ratings for Cluster-randomized Trials

Figure 16 Risk of Bias Ratings by Bias Domain: Objective Outcomes (Cluster-randomized Trials)

Figure 17 Risk of Bias Ratings for Non-randomized Trials