# METHODS

## TOPIC DEVELOPMENT

This topic was requested by the VA Rehabilitation Research & Development Service (RR&D). The findings from this review will be used to inform the development of a new request for applications on adjunct interventions that promote long-term adherence to physical rehabilitation recommendations. This review may also inform rehabilitation clinicians and program leadership who seek to improve the long-term outcomes for patients with chronic musculoskeletal pain and functional impairment.

## KEY QUESTION

The following key question (KQ) was the focus of this review: Among adults with hip/knee osteoarthritis or chronic low back pain, do physical rehabilitation interventions, supplemented with 1 or more adjunct components to promote adherence, improve self-efficacy, adherence, or sustained functional improvements at ≥3 months after completing the rehabilitation program?

## ANALYTIC FRAMEWORK

The analytic framework shown in Figure 1 provides a conceptual overview of this review. For adults with hip/knee OA or chronic LBP who engage in physical therapy and rehabilitation programs, the goal is to experience sustained functional improvements. It is generally thought that in order to sustain these functional improvements over time, patients need to demonstrate a long-term commitment to the practice of the prescribed home exercise program. However, long-term adherence to prescribed home exercise is often a struggle for many individuals. Thus, there is the potential for interventions that promote long-term adherence to be delivered as an adjunct to a standard rehabilitation program delivered either at the same time as the initial, or index, rehabilitation program (ie, concurrently) or after the end of the index program (ie, sequentially). An expected intermediate outcome of adjunct interventions that promote long-term adherence is increased self-efficacy to complete the home exercise program as prescribed. We also recognize that it is possible that there could be adverse effects from the addition of adjunct adherence interventions to rehabilitation programs, though we expect such effects to be rare. The analytic framework depicted in Figure 1 is a visual representation of the context for this report and highlights the intermediate and long-term outcomes of interest.

Figure 1 Analytic Framework

## DEFINITIONS

To guide our review process and reporting of findings, we established the following definitions:

- [underlined: Index rehabilitation program] is the initial physical rehabilitation care (ie, active, structured physical activity or activities designed to reduce impairments and improve movement-related function) that is delivered, supervised, and/or monitored by a health care professional or other trained individual.
- [underlined: Adjunct adherence-enhancing intervention] is the supplemental component provided to the patient in addition to the index rehabilitation program (either concurrent with or sequential to) that is designed to promote long-term adherence to the prescribed home rehabilitation practice.

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42021276794). There were no significant deviations after submission of this protocol. In addition, we followed the Preferred Reporting Items for Systematic Reviews and Meta Analyses (PRISMA) guideline.^12^

## DATA SOURCES AND SEARCHES

To identify primary literature that addresses our key question, we conducted a primary search from inception to July 27, 2021, in MEDLINE (via Ovid), CINAHL Complete (via EBSCO), and Embase (via Elsevier). We used database-specific controlled vocabulary as well as relevant keywords to search titles and abstracts (see Appendix A for complete search strategies). To ensure completeness, our search strategies were developed by an expert medical librarian (SC) with input on key terms from subject matter experts. We identified exemplar articles to use to test the integrity of our developed search strategy prior to executing across all databases. All search strategies were reviewed by a second medical librarian in accordance with the Peer Review of Electronic Search Strategies (PRESS) guideline.^13^

## STUDY SELECTION

Studies identified through our primary search were classified independently by investigators for relevance to the KQ based on our eligibility criteria (Table 1). All citations classified for possible inclusion based on title and abstract by at least 1 investigator underwent full-text review. Citations designated for exclusion by 1 investigator at the title-and-abstract level underwent screening by a second investigator. The study was excluded if both investigators agreed on exclusion. All articles reviewed during full-text review were evaluated independently by 2 investigators, and all articles meeting eligibility criteria were included for data abstraction. All articles were tracked in both DistillerSR, a web-based data synthesis software program (Evidence Partners Inc., Manotick, ON, Canada), and EndNote reference management software (Clarivate).

### Eligibility Criteria

Our review included studies that met the criteria shown in Table 1.

Table 1 Study Eligibility

| Inclusion | Exclusion
Populations | Adults (age 18 years+) with:; - Hip or knee osteoarthritis (self-reported diagnosis, clinical criteria, or radiographic evidence); - Chronic low back pain (lasting ≥12 weeks)^14^ | - <75% participants with hip or knee OA and/or chronic low back pain; - Patients with OA of hip/knee who are within 12 months before or after joint surgery
Interventions | Physical rehabilitation interventions (ie, active, structured physical activity or activities designed to reduce impairments and improve movement-related function that is delivered, supervised, and/or monitored by a health care professional or other trained individual) that have an adjunct component(s) (embedded within initial physical rehabilitation) or are followed by component(s) (delivered after initial physical rehabilitation) designed to promote long-term adherence to the prescribed rehabilitation home practice including but not limited to the following approaches:; - Feedback and monitoring (eg, use of activity monitors, automated text messages); - Social support (eg, peer coaches); - Incentives; - Psychologically informed interactions (eg, cognitive behavioral therapy, acceptance and commitment therapy, motivational interviewing); Initial rehabilitation intervention must be delivered by trained individuals (in-person or virtual) with clearly stated profession (eg, PTs, kinesiotherapists, certified exercise physiologist, physiatrist [rehabilitation MD]); Adherence-focused sessions/component delivered in addition to the core physical rehabilitation treatment may be delivered by individuals other than those who delivered the original physical rehabilitation treatment; Interventions may involve caregiver, but primary target of intervention must be the patient | Interventions focused on adherence to prescribed activities during initial rehabilitation treatment only; Interventions focused on perioperative rehabilitation for knee or hip replacement or other surgery
Comparators | Same initial physical rehabilitation intervention without the adjunct component or same initial physical rehabilitation with attention control instead of adjunct component | No comparator, other active comparator
Outcome | Any of the following if measured at 3 or more months after the end of the initial rehabilitation intervention:; - Self-efficacy to engage in home practice of physical rehabilitation outside of supervised physical rehabilitation; - Adherence to prescribed rehabilitation home practice; NOTE: If study does not explicitly describe an intent to promote long-term adherence to rehabilitation home practice, it must measure [underlined: adherence] as an outcome.; - Measures of physical function (including but not limited to WHO-DAS, FIM + FAM, 6-minute walk test); - Adverse events (eg, falls, fractures, ED visits) | Any outcomes without at least 1 of those listed under inclusion
Setting | Initial physical rehabilitation intervention: clinic or home-based; Adjunct component: in-person, home-based, remotely delivered) | Inpatient settings
Timing | At least 2 contacts for initial physical rehabilitation intervention | Not applicable
Study design | - Randomized trials; - Non-randomized trials | - Not a clinical study (eg, editorial, letter to an editor); - Uncontrolled clinical study; - Qualitative studies; - Prospective or retrospective observational studies; - Systematic review/meta-analysis; - Clinical guidelines; - Measurement or validation studies
Countries | OECD^a^ | Non-OECD
Publication types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

Notes.

a OECD includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, the United Kingdom, and the United States.

Abbreviations. ED=emergency department; FIM + FAM=Functional Independence Measure and Functional Assessment Measure; OA=osteoarthritis; OECD=Organisation for Economic Co-operation and Development; PT= Physical Therapist; WHO-DAS=World Health Organization Short Disability Assessment Schedule.

## DATA ABSTRACTION AND ASSESSMENT

Data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus. Abstracted data elements included participant descriptors (eg, age, sex, race/ethnicity, Veteran status), intervention characteristics (eg, interventionist profession, duration of index rehabilitation program, content and mode of both index rehabilitation program and adjunct component, whether adjunct component was delivered concurrently or in series to the initial index rehabilitation treatment course), comparator, and outcomes (eg, which outcome was identified as the primary outcome of the study). Multiple published reports analyzing data obtained from a single study were treated as a single data point with the most relevant results drawn across reports. When critical data were missing or unclear in published reports, we requested supplemental data from the study authors. For details of study characteristics, see Appendix B. Appendix C presents details of the intervention characteristics. Appendix D lists excluded studies and the reason for exclusion.

Quality assessment was completed in duplicate by 2 investigators (the investigator who abstracted the included article and the investigator who over-read the abstraction data). Disagreements were resolved by consensus between those 2 investigators or, as needed, by arbitration by a third investigator. We used the revised Cochrane Risk of Bias for randomized trials and cluster randomized trials (RoB 2)^15^ and the ROBINS-I for non-randomized studies.^16^ The domains for the RoB 2 include (1) bias arising from randomization process; (2) deviations from intended intervention; (3) missing outcome data; (4) bias in measurement of the outcome; and (5) bias in selection of the reported results. Overall risk of bias (ROB) judgments included low ROB, some concerns, and high ROB. Cluster-randomized studies were evaluated additionally for bias arising from the timing of identification and recruitment of individual participants in relation to timing of randomization. The ROBINS-I includes domains for (1) confounding; (2) participant selection; (3) intervention classification; (4) deviations from intended interventions; (5) missing data; (6) outcome measurement; and (7) selective outcome reporting. Overall ROB judgments included low ROB, serious ROB, critical ROB, and no information.

## SYNTHESIS

First, we summarized the following key study characteristics of the included studies: study design, patient demographics, details of the index rehabilitation program, adjunct adherence intervention and comparator, outcomes measures, and timing of outcomes assessment. We considered the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary effects. For meta-analyses, feasibility depends on the volume of relevant literature, conceptual homogeneity of the studies, and completeness of results reporting. Because of incomparability in intervention characteristics (eg, training for physical therapists in communication skills vs text message exercise reminders to patients) and delivery methods (eg, in-person vs automated), as well as inconsistency in outcome measurement, we did not conduct meta-analyses.

As an alternative to meta-analyses, we calculated the standardized mean difference (SMD) for studies reporting similar outcome categories (eg, functional status using a validated tool) when possible. Standardized mean differences for functional outcomes were calculated as the difference in mean change from the end of rehabilitation program between arms (intervention minus control) divided by the pooled standard deviation across the arms. When mean change was not reported by a study, we used difference between means at 2 time points and considered 0.5 correlation between measurements at these 2 time points to compute standard deviation of change. When values at the end of the rehabilitation program were not directly provided by a study, we computed these values based on the baseline mean values and reported mean change from baseline. Standardized mean differences for adherence outcomes were calculated as difference between arms (intervention minus control) at the time of follow-up measurement divided by the pooled standard deviation across the arms.

The follow-up timepoints of interest for this review are limited to outcomes at ≥ 3 months after completing the index rehabilitation program. We estimated the time point of each outcome measurement as time since baseline minus the time since end of the rehabilitation program (eg, data at 6 months after baseline is the same as data collected 3 months after a 3-month intervention). In cases where the study performed a second round of randomization after the end of the rehabilitation program and before implementation of adjunct adherence components, outcome time points are not changed, as baseline and end of the rehabilitation program are the same.

Because quantitative synthesis was not feasible, we analyzed data narratively through descriptive approaches that identify patterns in key outcomes, comparators, intervention approaches, and other study characteristics. We gave more weight to the evidence from higher quality studies with more precise estimates of effect. The narrative synthesis focused on documenting and identifying patterns in efficacy across included studies by outcome category (ie, adherence, functional status, self-efficacy, and adverse events). We analyzed potential reasons for inconsistency in treatment effects across studies by evaluating differences in the study population, intervention, comparator, and outcome definitions.

In addition, for each included study, we coded BCTs used in all experimental and control arms using a BCT taxonomy (v1)^10^ derived from information presented in included studies and any published protocols we identified. Two experienced reviewers (KS and ZR) independently coded each study for BCTs. Any discrepancies were resolved through discussion. A third author (KG) was consulted if needed.

Finally, the certainty of evidence (COE) was assessed using the approach described by the Grading of Recommendations Assessment, Development, and Evaluation (GRADE) working group.^17^ GRADE criteria require assessment of 4 domains: risk of bias, consistency, directness, and precision. Additional domains to be used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and a summary rating was assigned after discussion by a group of investigators (ZR, KS, KG, AG) as high, moderate, low, or very low COE. Randomized and non-randomized designs were not combined per GRADE guidance. Studies reporting dichotomous outcomes were not combined with studies reporting continuous outcomes.