# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) is responding to a request from the Rehabilitation Research and Development Service (RR&D). Findings from this review will be used to inform future research on adjunct interventions to promote long-term adherence to physical rehabilitation recommendations.

## BACKGROUND

Chronic pain, with musculoskeletal dysfunction as a common cause, results in over $600 billion of US health care spending annually—exceeding costs for other highly prevalent conditions like heart disease, cancer, and diabetes.^1^ Chronic low back pain (LBP), specifically, fell into the highest category of national health care spending in 2016.^2^ In the Veterans Health Administration (VHA), 25% of patients with musculoskeletal conditions receive care for LBP annually, and an additional 21% of Veterans receiving musculoskeletal care have osteoarthritis (OA). One approach to managing the symptoms of these chronic conditions is physical rehabilitation. Physical rehabilitation interventions use tailored exercise and activity to improve clinical outcomes for individuals with chronic LBP and OA, reducing pain and disability in these populations.^3,4^ Despite the effectiveness of rehabilitation, adherence to rehabilitation interventions has been measured as low as 13%. Poor adherence is a concern especially when the patient is no longer under direct clinical supervision.^5,6^

Adjunct interventions have been proposed to address low rates of long-term adherence to musculoskeletal rehabilitation by targeting the maintenance of, rather than initiation of, behavior change required for long-term success.^7^ Examples of adjuncts include psychological interventions (eg, cognitive behavioral therapy and motivational interviewing) and performance feedback interventions (eg, coaching, peer support, activity tracking^8^). However, it is currently unknown which of these adjunct interventions have the greatest impact on patient motivation, long-term adherence to rehabilitation, or ultimate physical function outcomes. This is largely due to a pervasive disconnect between components of behavior change interventions and the underlying mechanisms of behavior change (capability, opportunity, and motivation).^9^ Thus, there is an opportunity to improve long-term patient rehabilitation outcomes by applying current behavior change science—codified in the standardized, evidence-based behavior change technique (BCT) taxonomy^10^—to the analysis and design of long-term adherence interventions.

Promoting long-term physical function and quality of life in Veterans through evidence-based practice is a core goal of the VHA, and improving long-term adherence to rehabilitation for those with chronic musculoskeletal conditions has the potential to significantly delay or prevent severe forms of disease and disability.^11^ Thus, the aim of this review is to evaluate the impact of physical rehabilitation interventions supplemented with 1 or more adherence-focused adjunct components, on the following outcomes among adults with hip or knee OA or chronic LBP: (1) adherence, (2) functional improvements, and (3) self-efficacy at ≥ 3 months after completing an index rehabilitation program. As part of our analysis, we seek to provide insights into how future interventions might be optimized through the selection of BCTs that maximize patient benefit.