# APPENDIX G BEHAVIOR CHANGE TECHNIQUES USED IN INCLUDED STUDIES

Please refer to the main report’s reference list for full citations.

Cluster | BCT | Number of Interventions BCT Is Present In | Studies
Goals and planning | 1.1 Goal setting (behavior) | 10 (100%) | ^18^ ^–^ ^27^
Goals and planning | 1.2 Problem solving | 10 (100%) | ^18^ ^–^ ^27^
Goals and planning | 1.3 Goal setting (outcome) | 1 (10%) | ^20^
Goals and planning | 1.4 Action planning | 9 (90%) | ^19^ ^–^ ^27^
Goals and planning | 1.5 Review behavior (goals) | 4 (40%) | ^21^ ^,^ ^23^ ^,^ ^25^ ^,^ ^26^
Goals and planning | 1.8 Behavioral contract | 2 (20%) | ^22^ ^,^ ^27^
Feedback and monitoring | 2.1 Monitoring of behavior by others without feedback | 1 (10%) | ^20^
Feedback and monitoring | 2.2 Feedback on behavior | 8 (80%) | ^19^ ^,^ ^20^ ^,^ ^22^ ^–^ ^27^
Feedback and monitoring | 2.3 Self-monitoring of behavior | 8 (80%) | ^18^ ^,^ ^20^ ^–^ ^22^ ^,^ ^24^ ^–^ ^27^
Feedback and monitoring | 2.4 Self-monitoring of outcome of behavior | 1 (10%) | ^20^
Social support | 3.1 Social support (unspecified) | 3 (30%) | ^19^ ^–^ ^21^
Shaping knowledge | 4.1 Instruction on how to perform a behavior | 10 (100%) | ^18^ ^–^ ^27^
Shaping knowledge | 4.4 Behavioral experiments | 1 (10%) | ^20^
Natural consequences | 5.1 Information about health consequences | 7 (70%) | ^18^ ^–^ ^27^
Natural consequences | 5.2 Salience of consequences | 1 (10%) | ^27^
Comparison of behavior | 6.1 Demonstration of the behavior | 10 (100%) | ^18^ ^–^ ^27^
Comparison of behavior | 6.2 Social comparison | 1 (10%) | ^20^
Associations | 7.1 Prompts/cues | 2 (20%) | ^20^ ^,^ ^27^
Associations | 7.7 Exposure | 1 (10%) | ^19^
Repetition and substitution | 8.1 Behavioral practice/rehearsal | 10 (100%) | ^18^ ^–^ ^27^
Repetition and substitution | 8.2 Behavior Substitution | 1 (10%) | ^19^
Repetition and substitution | 8.3 Habit formation | 1 (10%) | ^20^
Repetition and substitution | 8.6 Generalization of a target behavior | 9 (90%) | ^19^ ^–^ ^27^
Repetition and substitution | 8.7 Graded tasks | 9 (90%) | ^19^ ^–^ ^27^
Comparison of outcomes | 9.1 Credible source | 9 (90%) | ^18^ ^–^ ^21^ ^,^ ^23^ ^–^ ^27^
Comparison of outcomes | 9.2 Pros and cons | 1 (10%) | ^19^
Comparison of outcomes | 9.3 Comparative imagining of future outcomes | 1 (10%) | ^19^
Reward and threat | 10.1 Material incentive (behavior) | 1 (10%) | ^18^
Reward and threat | 10.3 Non-specific reward | 1 (10%) | ^27^
Reward and threat | 10.9 Self-reward | 1 (10%) | ^20^
Reward and threat | 10.11 Future punishment | 1 (10%) | ^27^
Regulation | 11.2 Reduce negative emotions | 1 (10%) | ^21^
Antecedents | 12.1 Restructuring the physical environment | 1 (10%) | ^20^
Antecedents | 12.4 Distraction | 1 (10%) | ^20^
Identify | 13.5 Identity associated with changed behaviors | 1 (10%) | ^19^
Self-belief | 15.1 Verbal persuasion about capability | 2 (20%) | ^27^
Self-belief | 15.3 Focus on past success | 1 (10%) | ^20^
Self-belief | 15.4 Self-talk | 1 (10%) | ^20^