# APPENDIX F BEHAVIOR CHANGE TECHNIQUES USED IN INCLUDED STUDIES BY INTERVENTION AND COMPARATOR GROUPS

Please refer to the main report’s reference list for full citations.

Study | Index Rehabilitation Program | | Adjunct Adherence-Enhancing Intervention
Concurrently Delivered Adjunct Adherence
Bennell 2020^20^ | Goals and planning (1.1,1.4); Feedback and monitoring (2.1,2.2,2.3); Shaping knowledge (4.1) | Comparison of behavior (6.1); Repetition and substitution (8.1,8.6,8.7); Comparison of outcomes (9.1) | Goals and planning (1.2,1.3); Feedback and monitoring (2.4); Social support (3.1); Shaping knowledge (4.4); Natural consequences (5.1); Comparison of behavior (6.2); Associations (7.1) | Repetition and substitution (8.3); Reward and threat (10.9); Antecedents (12.1,12.4); Self-belief (15.1,15.3,15.4)
Baker 2020^21^ | Goals and planning (1.1,1.4); Feedback and monitoring (2.3); Shaping knowledge (4.1); Comparison of behavior (6.1) | Repetition and substitution (8.1,8.6,8.7); Comparison of outcomes (9.1) | Goals and planning (1.2,1.5); Social support (3.1); Natural consequences (5.1); Regulation (11.2)
Quicke 2017^22^ | Goals and planning (1.1,1.4); Feedback and monitoring (2.2); Shaping knowledge (4.1) | Comparison of behavior (6.1); Repetition and substitution (8.1); Generalization of a target behavior (8.6) | Goals and planning (1.2,1.8); Feedback and monitoring (2.3); Generalization of a target behavior (8.7)
Bennell 2014^23^ | Goals and planning (1.1,1.4); Feedback and monitoring (2.2); Shaping knowledge (4.1); Comparison of behavior (6.1) | Repetition and substitution (8.1,8.6,8.7); Comparison of outcomes (9.1) | Goals and planning (1.2,1.5)
Sequentially Delivered Adjunct Adherence
Lonsdale 2017^24^ | Goals and planning (1.1,1.4); Feedback and monitoring (2.2); Shaping knowledge (4.1); Comparison of behavior (6.1) | Repetition and substitution (8.1,8.6,8.7); Comparison of outcomes (9.1) | Goals and planning (1.2); Feedback and monitoring (2.3); Natural consequences (5.1)
Ben-Ami 2017^19^ | Goals and planning (1.1,1.4); Feedback and monitoring (2.2); Feedback and monitoring (4.1); Comparison of behavior (6.1) | Repetition and substitution (8.1,8.6,8.7); Comparison of outcomes (9.1) | Goals and planning (1.2); Social support (3.1); Natural consequences (5.1); Associations (7.7) | Repetition and substitution (8.2); Comparison of outcomes (9.2,9.3); Identify (13.5)
Bennell 2017^25^ | Goals and planning (1.1,1.4); Feedback and monitoring (2.2,2.3); Shaping knowledge (4.1); Natural consequences (5.1) | Comparison of behavior (6.1); Repetition and substitution (8.1,8.6,8.7); Comparison of outcomes (9.1) | Goals and planning (1.2,1.5); Feedback and monitoring (2.3)
Brosseau 2012^18^ | Feedback and monitoring (2.3); Shaping knowledge (4.1); Comparison of behavior (6.1); Repetition and substitution (8.1); Reward and threat (10.1) | | Goals and planning (1.1,1.2); Natural consequences (5.1); Comparison of outcomes (9.1)
Pisters 2010^26^ | Goals and planning (1.1,1.4,1.5); Feedback and monitoring (2.2); Shaping knowledge (4.1) | Comparison of behavior (6.1); Repetition and substitution (8.1,8.68.7); Comparison of outcomes (9.1) | Goals and planning (1.2); Feedback and monitoring (2.3)
Friedrich 1998^27^ | Feedback and monitoring ( 2.2); Shaping knowledge (4.1); Natural consequences (5.1); Comparison of behavior (6.1) | Repetition and substitution (8.1,8.6,8.7); Comparison of outcomes (9.1) | Goals and planning (1.1,1.2,1.4,1.8); Feedback and monitoring (2.3) | Natural consequences (5.2); Associations (7.1); Reward and threat (10.3,10.11); Self-belief (15.1)

Notes. Behavior change technique domains: 1.1 Goal setting (behavior); 1.2 Problem solving; 1.3 Goal setting (outcome); 1.4 Action planning; 1.5 Review behavior (goals); 1.8 Behavioral contract; 2.1 Monitoring of behavior by others without feedback; 2.2 Feedback on behavior; 2.3 Self-monitoring of behavior; 2.4 Self-monitoring of outcome of behavior; 3.1 Social support (unspecified); 4.1 Instruction on how to perform a behavior; 4.4 Behavioral experiments; 5.1 Information about health consequences; 5.2 Salience of consequences; 6.1 Demonstration of the behavior; 6.2 Social comparison; 7.1 Prompts/cues; 7.7 Exposure; 8.1 Behavioral practice/rehearsal; 8.2 Behavior Substitution; 8.3 Habit formation; 8.6 Generalization of a target behavior; 8.7 Graded tasks; 9.1 Credible source; 9.2 Pros and cons; 9.3 Comparative imagining of future outcomes; 10.1 Material incentive (behavior); 10.3 Non-specific reward; 10.9 Self-reward; 10.11 Future punishment; 11.2 Reduce negative emotions; 12.1 Restructuring the physical environment; 12.4 Distraction; 13.5 Identity associated with changed behaviors; 15.1 Verbal persuasion about capability; 15.3 Focus on past success; 15.4 Self-talk.

Abbreviations. BCT=Behavior Change Techniques.