# APPENDIX E PEER REVIEW DISPOSITION

Question Text | Reviewer Number | Comment | Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes
Are the objectives, scope, and methods for this review clearly described? | 2 | Yes
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes
Are the objectives, scope, and methods for this review clearly described? | 6 | Yes
Is there any indication of bias in our synthesis of the evidence? | 1 | No
Is there any indication of bias in our synthesis of the evidence? | 2 | No
Is there any indication of bias in our synthesis of the evidence? | 3 | No
Is there any indication of bias in our synthesis of the evidence? | 4 | No
Is there any indication of bias in our synthesis of the evidence? | 5 | No
Is there any indication of bias in our synthesis of the evidence? | 6 | No
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | No
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 2 | No
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 3 | No
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 4 | No
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 5 | No
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 6 | No
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Executive Summary, Key Findings Page 11, 3rd bullet from top, and on page 14 key findings and strength of evidence - report states “…overlap in behavior change techniques with comparator arms” - Were rationales provided in the study publications on why the BCT overlap between arms? Or adherence/maintenance was not the primary aim of the trial? | We appreciate this important question. Five of the 10 unique included studies had adherence as a primary outcome or aim of the study. Of these, only one study (Bennell et al)^20^ mentions that the intervention development was informed by the BCTs and related theory. No studies provide a rationale for the overlap. We have added this to the executive summary and the main body of the report (Key Findings and Discussion sections).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Executive summary Page 11 - 7th bullet - appears to be a typo - says “imitation’” Should it be “initiation?” | Thank you, this typo has been corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Page 12: intervention characteristics - all were PTs who delivered intervention - did the research report training/knowledge/experience of PT in behavior change techniques? Did any of the final studies report fidelity or quality of delivery? | We agree that these are key details about the included studies that warrant reporting.; Little information was provided about the training of the physical therapy interventionists. Only three studies mentioned PT training and they reported on the standard of care training.^19,24,27^ None reported training specifically about PT knowledge or familiarity with BCTs. A comment was added about this lack of available detail (see Executive Summary and main report in Intervention Characteristics sections).; All but one study^18^ provided some information about fidelity to intervention protocol, though the method of reporting fidelity was variable. There was no clear pattern between higher reported fidelity and intervention effect. We have added this information to Appendix C.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Page 15 - Lines 20-23 “Overall we determined there was low certainty that adjunctive intervention components have no effect on the adherence…….” THIS IS A CONFUSING STATEMENT -do you mean your team could not conclude that actually no effect exists on adherence or low certainty of any effect existing on adherence?? | We have clarified the wording of the certainty of evidence statement in the key findings and strength of evidence section of the executive summary to read:; “Overall, based on GRADE criteria, we found low certainty of evidence that there is no effect of adjunctive interventions on adherence…”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Page 25 lines 12 - we analyzed data narratively?? What does that mean? | We have reworded this section of the data synthesis methods in the executive summary for clarity and the passage now reads as follows:; “Because quantitative synthesis was not feasible, we analyzed data narratively through descriptive approaches which identify patterns in key outcomes, comparators, intervention approaches, and other study characteristics.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | PAge 29 Behavior Change Techniques How was goal setting utilized? Were these clinical goals or patient self management goals? Support? The report includes very little details on the operationalization of BCTs. The authors do state often BCTs were insufficiently described in papers. (page 57) | The Behavior Change Technique Taxonomy provides extensive definitions of each of the 93 individual BCTs. There are multiple specific techniques for goal setting. For example, BCT 1.1 is related to behavioral goal setting while BCT 1.3 described a goal focused on a specific outcome. While it is beyond the scope of this report to provide granular detail about each technique, we would refer readers to the reference by Mitchie et al^10^ for more extensive definitions. We have also added text noting that there was little detail about how individual BCTs were operationalized across the included studies (see BCT section in main report results).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | PAge 30 - line #16 - What is covert learning? Is this vicarious learning? | The BCT cluster “covert learning” includes BCTs for imaginary punishment, imaginary reward, and vicarious consequences. Further detail can be found in Michie et al^10^
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Overall, the authors performed rigorous methods with a limited set of eligible trials. | Thank you
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | This manuscript focused on synthesizing the evidence regarding interventions to improve long-term adherence to physical rehabilitation among adults with hip or knee osteoarthritis or chronic low back pain. Overall, this was a well-written review and the authors used rigorous study selection and review methods. Most of my comments (outlined below) focus on additional contextualization of the literature or revisions for clarity/readability. | Thank you
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 1. What was the length of intervention provided (not just time to the follow-up assessment) for each sequentially delivered adjunct adherence intervention (some of this info is in the appendix, but it would be helpful to have it in the main paper)? For example, it is described that the Bennell et al study (which showed an effect) was delivered weekly for 24 weeks, which represents weekly contact throughout the 6-month follow-up period. Another intervention is described as including two booster sessions; however, the frequency/duration of contact in the other studies is not described. This might be important as, in other health behavior change areas, the amount and continued nature of contact appears to be critical for promoting maintenance (e.g., in research on obesity treatment programs, provision of continued follow-up by an interventionist has been shown to promote long-term weight loss maintenance; however this effect disappears when extended-care interventions end, suggesting that a chronic disease/continuous care model may be more appropriate for continued promotion of weight loss maintenance). It would be helpful to investigate whether the frequency/duration of contact was associated with stated outcomes, and highlight this as an area of future research if a gap is identified. | We agree fully that intervention dose plays an important role in behavior maintenance. The duration of contact across the sequentially delivered interventions was 6 months for 3 of the 4 sequential studies and 2 years for the 4^th^. The frequency of contact during the intervention period ranged from 2 contacts over 6 months to 42 contacts over 2 years. As noted by the reviewer, the one sequentially delivered intervention that showed an effect was Bennell et al.^20^ We have moved this information from the appendix into the Intervention Characteristics section of the Executive Summary and main report.; Regarding the importance of the association between intervention dose and outcomes, we are unable to consider any subgroup analysis by this design feature given the small number of identified studies relevant to this question. We agree that it should be noted as a gap for future research. We have added this to the future research sections (see Table 8).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 2. The authors cite the Voils paper (citation 7) in several places to back up the argument that maintenance of behavior change requires fundamentally different skills than those used for initiation of behavior change. Although this has been argued in relation to several health behaviors, there still exists limited / preliminary data to back up this model. The Voils paper cited is only a pilot trial and by itself does not provide the level of evidence necessary to support this argument as it is written in the paper. Consider presenting more nuance within this argument, highlighting gaps in this area as another potential area for future research. | We appreciate the reviewer’s comment and agree we did not provide full support for our argument. While the study of Voils et al that we cited is a pilot study, it is one that incorporated over a decade of research and foundational thought into the development of a new framework. Examples of prior work contributing to this concept including work by Kwasnicka et al, Greaves et al, and Howlett et al.^13,39–41^ In addition, the framework from Voils’ paper has been subsequently used in well-powered trials which have gone on to demonstrate positive effect (Voils et al, 2017).^37,38^ We have added these citations to the discussion section of the main report as well.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | Other comments by section:; 3. Data synthesis, page 14: the authors note “standardized mean differences…were calculated as the difference in change from the end of rehabilitation program between arms.” Please clarify how these were calculated (e.g., typically this means dividing means by SDs, was this done? Were SDs available in all articles?). For which studies were all data available and for which did you have to make assumptions based on baseline data? | We have added further details to the methods section describing how standardized mean differences were calculated for all studies in forest plots using the pooled standard deviation.; One study^23^, provided SD as a function of change directly. For all other studies, we computed SD of change from after-treatment to follow-up assuming correlation of 0.5 between after-treatment SD and follow-up SD.; For two studies^19,24^, we used mean change from baseline to after-treatment and the baseline mean (and corresponding SDs) to compute after-treatment mean change and SD (assuming 0.5 correlation between baseline and after-treatment measurements). We computed follow-up mean and SD the same way. Details have been added to the Key Outcomes of Interest results section of the main report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 4. The discussion describes issues with missing outcome data; however, it is unclear from the results how much data were missing and whether missing data procedures were used (this could also represent another important future direction for research). | Thank you, we have highlighted missing data as a key contributor to study ratings of high risk of bias in the quality of the evidence section of the results.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 5. Also in the discussion, it would be helpful to provide more information on the categories of BCTs/individual BCTs that were not included in reviewed interventions as potential areas for future research. | We discuss categories of BCTs that may be useful for future research that were not well represented in our included studies in the “Future Intervention Design Considerations” on page 65. Some examples include social support, behavioral contracts, intention to perform exercises, and the use of rewards.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 6. In Appendix E, it would be helpful to provide more detail on what each BCT is (vs. just giving the #) so that readers do not have to reference another paper to understand which BCTs were included/which were excluded. | Thank you, the BCT domains have been added to this appendix (Appendix F in the final report).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 7. Figure 1: I find this figure confusing / hard to follow – I’m not sure what it adds beyond the text, and the use of boxes and arrows could potentially mislead readers to assume that moderation and mediation pathways are being described (these may be appropriate, but should be discussed in the text as well). | For our reports, we include a visual representation of an analytic framework, as opposed to a conceptual model, using standardized nomenclature for systematic reviews. We agree that the previous version was somewhat confusing and could be interpreted to imply that the listed intermediate outcomes were mediators of the distal health outcomes. We have reworked this figure and clarified the associated text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 8. Table 7: I do not understand why there are studies separated out within rows (e.g., under adherence 3 to 6 months, 4 RCTs are in one row while another RCT is in another); shouldn’t certainty of evidence summarize certainty across ALL of these studies, combined? | Thank you. Randomized and nonrandomized designs are not combined as per GRADE guidance.^17^ Studies reporting dichotomous outcomes could not be combined with studies reporting continuous outcomes. This clarification has been added to the report (rating the body of evidence methods section and table 7 notes).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 9. Table 8: The first bullet point is a full sentence but the remaining bullet points are not; it would be helpful for readability to pick one format and stick with it. Similarly, some of the bullet points identify gaps (missing research in the field) while others seem more like they are suggesting solutions (e.g., suggesting specific new areas). Consider clarifying how gaps are described (for further clarification between the two, could a column of “future directions” be added to the table?). | Thank you, we have standardized the bullet point formatting and clarified the language.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | Other minor comments:; 10. Acronyms are used before they are defined (e.g., use of OA, ROB, BCTs, SMD in the executive summary). PICOTS is undefined. | Thank you. We have added expansions for the acronyms.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | 11. There are some typos/grammatical mistakes (I’ve identified some below); the manuscript would benefit from close proofing. For example:; - The final bullet point in the executive summary: did the authors mean to write that “focus of differences in initiation” vs “imitation”? In this same bullet point, modifying “tailoring” to “tailor” would promote readability via parallel format across each recommendation.; - Readability would be improved by consistently writing out or using numerals consistently (e.g., “two investigators” vs “2 investigators” in Data Abstraction section on page 2).; - Readability would also be improved by consistent use of either active or passive voice.; - Page 47, line 21: there is an extra word (“studies did not have an a prior focus”) | Thank you. These typos have been addressed where necessary. The ESP style guide stipulates that numbers are written as numerals unless they appear at the start of a sentence.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - Page 3, line 52: adjective should be adjunctive | Thank you, we corrected this typo.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - Page 4, lines 51-54 requires further explanation – too vague | We have added further clarification by adding the specific models that specify conceptually distinct stages for initiation and long-term adherence.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - Page 47, line 21 “a prior” should be “a priori” | Thank you, we corrected this typo.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | - I think the conclusions and findings are logical based on the review. I have input about self-efficacy. There are many different self-efficacy scales and self-efficacy is behavior specific. For example, the Arthritis Self-Efficacy Scale assesses a person’s confidence in managing their condition (arthritis). It is a poor reflection of a person’s confidence to complete their exercise home program, yet I’m guessing it was used in some of the studies for this purpose. I also wonder if in the studies that measured self-efficacy, they included specific interventions to improve self-efficacy. I looked at one of the articles cited (Bennell et al, 2020) and it doesn’t appear to me that they included interventions to improve exercise self-efficacy, but it’s difficult to tell. The types of interventions that should be used to improve self-efficacy for exercise include mastery experiences, vicarious experiences, verbal persuasion, and affective states. While I’m not sure this information changes your results/conclusions, it is an observation you could include that has implications for future research. You did mention that several of the self-efficacy scales were not valid and reliable; I think you could also indicate that they may not have been well-matched for the intervention, and, the interventions did not employ specific approaches to enhance self-efficacy. The fact that numerous articles found no difference between self-efficacy scores in the control and experimental groups illustrates my point. | We agree that measures of self-efficacy should be specific to the behavior in question and those used by the included studies did not all align with adherence to a home exercise program. We included all related outcomes though acknowledge this is not ideal and have clarified this in the report under key points in the discussion section of the main report.; The reviewer raises an important point about the need for the inclusion of intervention components to promote self-efficacy related to completing recommended exercise regimens. At this point, there are no clear BCTs that have been identified which are clearly associated with improved self-efficacy though in the context of physical activities more BCTs seem to be associated with improved self-efficacy (Tang et al).^42^ We have added clarity around this limitation in the report and as an area for future research.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | I wonder about the compounding factor of face-to-face interventions vs. telephonic or text message interventions. It seems that you lumped all approaches together. If the literature indicates that there is no difference in outcomes comparing face-to-face interventions and telephonic/SMS/computer, then I think this is a sound approach. If the literature does not support no difference, then the difference needs to be teased out. | Because the literature in the field is nascent and the volume of studies is small, it is challenging to draw comparisons for outcomes related to the face-to-face vs telephonic/text message interventions. No studies made this direct comparison. We highlight this as an evidence gap to be further explored in Table 8.