# APPENDIX D EXCLUDED STUDIES

Exclude reasons: 1=Non-OECD, 2=Ineligible population, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible intervention, 5=Ineligible timing, 6=Ineligible study design.

Citation | Exclude Reason
Aliyu, 2018^1^ | 1
Bagheri, 2020^2^ | 1
Buchner, 2006^3^ | 2
Canaway, 2018^4^ | 4
Chen, 2020^5^ | 1
Chen, 2016^6^ | 2
Cheung, 2016^7^ | 3
Christiansen, 2020^8^ | 2
Christiansen, 2010^9^ | 4
Coppack, 2012^10^ | 6
Davergne, 2019^11^ | 2
De Oliveira Silva, 2020^12^ | 2
Elbadawy, 2017^13^ | 1
Focht, 2014^14^ | 3
Garver, 2011^15^ | 3
Gay, 2020^16^ | 3
George, 2010^17^ | 3
Geraghty, 2018^18^ | 5
Godges, 2008^19^ | 2
Gohner, 2006^20^ | 2
Hay, 2018^21^ | 7
Hugli, 2015^22^ | 5
Hunt, 2013^23^ | 4
Iles, 2011^24^ | 2
Jacobson, 2015^25^ | 5
Jensen, 2001^26^ | 2
Jensen, 2012^27^ | 3
Jessep, 2009^28^ | 3
Johansson, 2009^29^ | 2
Kaapa, 2006^30^ | 5
Karvannan, 2012^31^ | 1
Keefe, 2004^32^ | 4
Keefe, 1999^33^ | 5
Kerns, 2014^34^ | 3
King, 2008^35^ | 3
Krein, 2013^36^ | 3
Ledingham, 2020^37^ | 3
Li, 2020^38^ | 3
Lonsdale, 2012^39^ | 3
Marconcin, 2021^40^ | 5
Meng, 2017^41^ | 3
Monticone, 2021^42^ | 2
Nelligan, 2019^43^ | 7
Nelson, 2020^44^ | 2
Nicolson, 2018^45^ | 3
O’Brien, 2013^46^ | 4
O’Neill, 2020^47^ | 5
Palmer, 2014^48^ | 5
Patel, 2014^49^ | 4
Pelle, 2021^50^ | 3
Penttinen, 2002^51^ | 4
Pires, 2020^52^ | 3
Reilly, 1989^53^ | 5
Rejeski, 1997^54^ | 3
Rini, 2015^55^ | 3
Ronzi, 2017^56^ | 4
Şahin Onat, 2013^57^ | 4
Schiltenwolf, 2006^58^ | 5
Shimo, 2021^59^ | 4
Smeets, 2006^60^ | 5
Smeets, 2008^61^ | 3
Steinhilber, 2012^62^ | 2
Storro, 2004^63^ | 3
Suzuki, 2019^64^ | 2
Thomas, 2002^65^ | 5
Van Dillen, 2016^66^ | 2
van Dulmen, 2014^67^ | 1
Vong, 2011^68^ | 3
Walsh, 2013^69^ | 2
Willett, 2017^70^ | 3

## REFERENCES

1 Aliyu FY, Wasiu AA, Bello B. Effects of a combined lumbar stabilization exercise and cognitive behavioral therapy on selected variables of individuals with non-specific low back pain: A randomized clinical trial. Fisioterapia. 2018;40(5):257–264.
2 Bagheri R, Hedayati R, Ehsani F, Hemati-Boruojeni N, Abri A, Taghizadeh Delkhosh C. Cognitive Behavioral Therapy With Stabilization Exercises Affects Transverse Abdominis Muscle Thickness in Patients With Chronic Low Back Pain: A Double-Blinded Randomized Trial Study. Journal of Manipulative & Physiological Therapeutics. 2020;43(5):418–428.32928570
3 Buchner M, Zahlten-Hinguranage A, Schiltenwolf M, Neubauer E. Therapy outcome after multidisciplinary treatment for chronic neck and chronic low back pain: A prospective clinical study in 365 patients. Scandinavian Journal of Rheumatology. 2006;35(5):363–367.17062436
4 Canaway A, Pincus T, Underwood M, Shapiro Y, Chodick G, Ben-Ami N. Is an enhanced behaviour change intervention cost-effective compared with physiotherapy for patients with chronic low back pain? Results from a multicentre trial in Israel. BMJ Open. 2018;8(4):e019928.
5 Chen H, Wang Y, Liu C, . Benefits of a transtheoretical model-based program on exercise adherence in older adults with knee osteoarthritis: A cluster randomized controlled trial. Journal of Advanced Nursing. 2020;76(7):1765–1779.32202313
6 Chen M, Li P, Lin F. Influence of structured telephone follow-up on patient compliance with rehabilitation after total knee arthroplasty. Patient preference & adherence. 2016;10:257–264.27042020
7 Cheung C, Wyman JF, Savik K. Adherence to a Yoga Program in Older Women with Knee Osteoarthritis. Journal of Aging & Physical Activity. 2016;24(2):181–188.26214142
8 Christiansen MB, Thoma LM, Master H, . Feasibility and Preliminary Outcomes of a Physical Therapist–Administered Physical Activity Intervention After Total Knee Replacement. Arthritis Care and Research. 2020;72(5):661–668.30908867
9 Christiansen S, Oettingen G, Dahme B, Klinger R. A short goal-pursuit intervention to improve physical capacity: a randomized clinical trial in chronic back pain patients. Pain. 2010;149(3):444–452.20199846
10 Coppack RJ, Kristensen J, Karageorghis CI. Use of a goal setting intervention to increase adherence to low back pain rehabilitation: a randomized controlled trial. Clinical Rehabilitation. 2012;26(11):1032–1042.22357799
11 Davergne T, Pallot A, Dechartres A, Fautrel B, Gossec L. Use of Wearable Activity Trackers to Improve Physical Activity Behavior in Patients With Rheumatic and Musculoskeletal Diseases: A Systematic Review and Meta-Analysis. Arthritis Care and Research. 2019;71(6):758–767.30221489
12 De Oliveira Silva D, Pazzinatto MF, Crossley KM, Azevedo FM, Barton CJ. Novel Stepped Care Approach to Provide Education and Exercise Therapy for Patellofemoral Pain: Feasibility Study. Journal of Medical Internet Research. 2020;22(7):e18584.32706674
13 Elbadawy MA. Effectiveness of Periosteal Stimulation Therapy and Home Exercise Program in the Rehabilitation of Patients With Advanced Knee Osteoarthritis. Clinical Journal of Pain. 2017;33(3):254–263.27513639
14 Focht BC, Garver MJ, Devor ST, . Group-mediated physical activity promotion and mobility in sedentary patients with knee osteoarthritis: Results from the IMPACT-pilot trial. Journal of Rheumatology. 2014;41(10):2068–2077.25179854
15 Garver MJ. Improving Maintenance of Physical Activity Trial (IMPACT-P), Ohio State University; 2011.
16 Gay C, Guiguet-Auclair C, Coste N, . Limited effect of a self-management exercise program added to spa therapy for increasing physical activity in patients with knee osteoarthritis: A quasi-randomized controlled trial. Annals of Physical & Rehabilitation Medicine. 2020;63(3):181–188.31794857
17 George SZ, Wittmer VT, Fillingim RB, Robinson ME. Comparison of graded exercise and graded exposure clinical outcomes for patients with chronic low back pain. Journal of Orthopaedic & Sports Physical Therapy. 2010;40(11):694–704.20972340
18 Geraghty AWA, Stanford R, Stuart B, . Using an internet intervention to support self-management of low back pain in primary care: findings from a randomised controlled feasibility trial (SupportBack). BMJ Open. 2018;8(3):e016768.
19 Godges JJ, Anger MA, Zimmerman G, Delitto A. Effects of education on return-to-work status for people with fear-avoidance beliefs and acute low back pain. Physical Therapy. 2008;88(2):231–239.18056753
20 Gohner W, Schlicht W. Preventing chronic back pain: evaluation of a theory-based cognitive-behavioural training programme for patients with subacute back pain. Patient Education & Counseling. 2006;64(1–3):87–95.16540279
21 Hay E, Dziedzic K, Foster N, . NIHR Journals Library. Programme Grants for Applied Research. 2018;7:7.
22 Hugli AS, Ernst MJ, Kool J, . Adherence to home exercises in non-specific low back pain. A randomised controlled pilot trial. Journal of Bodywork & Movement Therapies. 2015;19(1):177–185.25603757
23 Hunt MA, Keefe FJ, Bryant C, . A physiotherapist-delivered, combined exercise and pain coping skills training intervention for individuals with knee osteoarthritis: a pilot study. Knee. 2013;20(2):106–112.22921688
24 Iles R, Taylor NF, Davidson M, O’Halloran P. Telephone coaching can increase activity levels for people with non-chronic low back pain: a randomised trial. Journal of Physiotherapy. 2011;57(4):231–238.22093121
25 Jacobson EE, Meleger AL, Bonato P, . Structural integration as an adjunct to outpatient rehabilitation for chronic nonspecific low back pain: a randomized pilot clinical trial. Evidence-Based Complementary & Alternative Medicine: eCAM. 2015;2015:813418.25945112
26 Jensen IB, Bergstrom G, Ljungquist T, Bodin L, Nygren AL. A randomized controlled component analysis of a behavioral medicine rehabilitation program for chronic spinal pain: are the effects dependent on gender? Pain. 2001;91(1–2):65–78.11240079
27 Jensen LD, Maribo T, Schiottz-Christensen B, . Counselling low-back-pain patients in secondary healthcare: a randomised trial addressing experienced workplace barriers and physical activity. Occupational & Environmental Medicine. 2012;69(1):21–28.21597108
28 Jessep SA, Walsh NE, Ratcliffe J, Hurley MV. Long-term clinical benefits and costs of an integrated rehabilitation programme compared with outpatient physiotherapy for chronic knee pain. Physiotherapy. 2009;95(2):94–102.19627690
29 Johansson AC, Linton SJ, Bergkvist L, Nilsson O, Cornefjord M. Clinic-based training in comparison to home-based training after first-time lumbar disc surgery: a randomised controlled trial. European Spine Journal. 2009;18(3):398–409.19020904
30 Kaapa EH, Frantsi K, Sarna S, Malmivaara A. Multidisciplinary group rehabilitation versus individual physiotherapy for chronic nonspecific low back pain: a randomized trial. Spine. 2006;31(4):371–376.16481945
31 Karvannan H, Maiya AG, Chakravarty RD, . Effectiveness of behavior graded activity on exercise adherence and physical activity in hip and knee osteoarthritis — A systematic review. Indian Journal of Rheumatology. 2012;7(3):141–146.
32 Keefe FJ, Blumenthal J, Baucom D, . Effects of spouse-assisted coping skills training and exercise training in patients with osteoarthritic knee pain: a randomized controlled study. Pain. 2004;110(3):539–549.15288394
33 Keefe FJ, Caldwell DS, Baucom D, . Spouse-assisted coping skills training in the management of knee pain in osteoarthritis: Long-term follow-up results. Arthritis Care and Research. 1999;12(2):101–111.10513498
34 Kerns RD, Burns JW, Shulman M, . Can we improve cognitive-behavioral therapy for chronic back pain treatment engagement and adherence? A controlled trial of tailored versus standard therapy. Health Psychology. 2014;33(9):938–947.24295024
35 King LK, Birmingham TB, Kean CO, Jones IC, Bryant DM, Giffin JR. Resistance training for medial compartment knee osteoarthritis and malalignment. Medicine & Science in Sports & Exercise. 2008;40(8):1376–1384.18614957
36 Krein SL, Kadri R, Hughes M, . Pedometer-based internet-mediated intervention for adults with chronic low back pain: randomized controlled trial. Journal of Medical Internet Research. 2013;15(8):e181.23969029
37 Ledingham A, Cohn ES, Baker KR, Keysor JJ. Exercise adherence: beliefs of adults with knee osteoarthritis over 2 years. Physiotherapy Theory & Practice. 2020;36(12):1363–1378.30652930
38 Li LC, Feehan LM, Xie H, . Effects of a 12-Week Multifaceted Wearable-Based Program for People With Knee Osteoarthritis: Randomized Controlled Trial. JMIR Mhealth and Uhealth. 2020;8(7):e19116.32618578
39 Lonsdale C, Hall AM, Williams GC, . Communication style and exercise compliance in physiotherapy (CONNECT): a cluster randomized controlled trial to test a theory-based intervention to increase chronic low back pain patients’ adherence to physiotherapists’ recommendations: study rationale, design, and methods. BMC Musculoskeletal Disorders. 2012;13:104.22703639
40 Marconcin P, Yazigi F, Teles J, Campos P, Espanha M. The effectiveness of a randomised clinical trial of PLE<sup>2</sup> NO self-management and exercise programme for knee osteoarthritis to improve self-efficacy. Musculoskeletal Care. 2021;02:02.
41 Meng K, Peters S, Faller H. Effectiveness of a standardized back school program for patients with chronic low back pain after implementation in routine rehabilitation care. Patient Education & Counseling. 2017;100(6):1161–1168.28110954
42 Monticone M, Ambrosini E, Portoghese I, Rocca B. Multidisciplinary program based on early management of psychological factors reduces disability of patients with subacute low back pain. Results of a randomised controlled study with one year follow-up. European journal of physical & rehabilitation medicine. 2021;05:05.
43 Nelligan RK, Hinman RS, Kasza J, . Effect of a short message service (SMS) intervention on adherence to a physiotherapist-prescribed home exercise program for people with knee osteoarthritis and obesity: protocol for the ADHERE randomised controlled trial. BMC Musculoskeletal Disorders. 2019;20(1):428.31521136
44 Nelson M, Bourke M, Crossley K, Russell T. Telerehabilitation is non-inferior to usual care following total hip replacement — a randomized controlled non-inferiority trial. Physiotherapy. 2020;107:19–27.32026820
45 Nicolson PJA, Hinman RS, French SD, Lonsdale C, Bennell KL. Improving Adherence to Exercise: Do People With Knee Osteoarthritis and Physical Therapists Agree on the Behavioral Approaches Likely to Succeed? Arthritis care & research. 2018;70(3):388–397.28575544
46 O’Brien D, Bassett S, McNair P. The effect of action and coping plans on exercise adherence in people with lower limb osteoarthritis: feasibility study. New Zealand Journal of Physiotherapy. 2013;41(2):49–57.
47 O’Neill A, O’Sullivan K, O’Sullivan P, Purtill H, O’Keeffe M. Examining what factors mediate treatment effect in chronic low back pain: A mediation analysis of a Cognitive Functional Therapy clinical trial. European Journal of Pain. 2020;24(9):1765–1774.32594587
48 Palmer S, Domaille M, Cramp F, . Transcutaneous electrical nerve stimulation as an adjunct to education and exercise for knee osteoarthritis: a randomized controlled trial. Arthritis care & research. 2014;66(3):387–394.23983090
49 Patel S, Ngunjiri A, Hee SW, . Primum non nocere: shared informed decision making in low back pain—a pilot cluster randomised trial. BMC Musculoskeletal Disorders. 2014;15:282.25146587
50 Pelle T, van der Palen J, de Graaf F, van den Hoogen FHJ, Bevers K, van den Ende CHM. Use and usability of the dr. Bart app and its relation with health care utilisation and clinical outcomes in people with knee and/or hip osteoarthritis. BMC Health Services Research. 2021;21(1):444.33971861
51 Penttinen J, Nevala-Puranen N, Airaksinen O, Jaaskelainen M, Sintonen H, Takala J. Randomized controlled trial of back school with and without peer support. Journal of Occupational Rehabilitation. 2002;12(1):21–29.11837056
52 Pires D, Cruz EB, Costa D, Nunes C. Beyond pain and disability: an explanatory mixed methods study exploring outcomes after physiotherapy intervention in patients with chronic low back pain. Disability & Rehabilitation. 2020:1–10.
53 Reilly K, Lovejoy B, Willams R, Roth H. Differences between a supervised and independent strength and conditioning program with chronic low back syndromes. Journal of Occupational Medicine. 1989;31(6):547–550.2525182
54 Rejeski WJ, Brawley LR, Ettinger W, Morgan T, Thompson C. Compliance to exercise therapy in older participants with knee osteoarthritis: implications for treating disability. Medicine & Science in Sports & Exercise. 1997;29(8):977–985.9268953
55 Rini C, Porter LS, Somers TJ, . Automated Internet-based pain coping skills training to manage osteoarthritis pain: a randomized controlled trial. Pain. 2015;156(5):837–848.25734997
56 Ronzi Y, Roche-Leboucher G, Begue C, . Efficiency of three treatment strategies on occupational and quality of life impairments for chronic low back pain patients: is the multidisciplinary approach the key feature to success? Clinical Rehabilitation. 2017;31(10):1364–1373.28592147
57 Şahin Onat S, Ünsal Delialioǧlu S, Uçar D. Exercises in the treatment of elderly patients with knee osteoarthritis: Factors affecting the efficiency of patient education. Turk Geriatri Dergisi. 2013;16(2):166–171.
58 Schiltenwolf M, Buchner M, Heindl B, Von Reumont J, Müller A, Eich W. Comparison of a biopsychosocial therapy (BT) with a conventional biomedical therapy (MT) of subacute low back pain in the first episode of sick leave: A randomized controlled trial. European Spine Journal. 2006;15(7):1083–1092.16311751
59 Shimo K, Hasegawa M, Mizutani S, Hasegawa T, Ushida T. Effects of a 12-week workplace counseling program on physical activity and low back pain: A pilot randomized controlled study. Journal of Back & Musculoskeletal Rehabilitation. 2021;30:30.
60 Smeets RJEM, Vlaeyen JWS, Hidding A, . Active rehabilitation for chronic low back pain: Cognitive-behavioral, physical, or both? First direct post-treatment results from a randomized controlled trial [ISRCTN22714229]. BMC Musculoskeletal Disorders. 2006;7.
61 Smeets R, Vlaeyen JWS, Hidding A, Kester ADM, van der Heijden G, Knottnerus AJ. Chronic low back pain: physical training, graded activity with problem solving training, or both? The one-year post-treatment results of a randomized controlled trial. Pain. 2008;134(3):263–276.17498879
62 Steinhilber B, Haupt G, Miller R, . Feasibility and efficacy of an 8-week progressive home-based strengthening exercise program in patients with osteoarthritis of the hip and/or total hip joint replacement: a preliminary trial. Clinical Rheumatology. 2012;31(3):511–519.22086491
63 Storro S, Moen J, Svebak S. Effects on sick-leave of a multidisciplinary rehabilitation programme for chronic low back, neck or shoulder pain: comparison with usual treatment. Journal of Rehabilitation Medicine. 2004;36(1):12–16.15074433
64 Suzuki Y, Iijima H, Tashiro Y, . Home exercise therapy to improve muscle strength and joint flexibility effectively treats pre-radiographic knee OA in community-dwelling elderly: a randomized controlled trial. Clinical Rheumatology. 2019;38(1):133–141.30167975
65 Thomas KS, Muir KR, Doherty M, Jones AC, O’Reilly SC, Bassey EJ. Home based exercise programme for knee pain and knee osteoarthritis: randomised controlled trial. BMJ. 2002;325(7367):752.12364304
66 Van Dillen LR, Norton BJ, Sahrmann SA, . Efficacy of classification-specific treatment and adherence on outcomes in people with chronic low back pain. A one-year follow-up, prospective, randomized, controlled clinical trial. Manual Therapy. 2016;24:52–64.27317505
67 van Dulmen SA, Maas M, Staal JB, . Effectiveness of peer assessment for implementing a Dutch physical therapy low back pain guideline: cluster randomized controlled trial. Physical Therapy. 2014;94(10):1396–1409.24830716
68 Vong SK, Cheing GL, Chan F, So EM, Chan CC. Motivational enhancement therapy in addition to physical therapy improves motivational factors and treatment outcomes in people with low back pain: a randomized controlled trial. Archives of Physical Medicine & Rehabilitation. 2011;92(2):176–183.21272712
69 Walsh N, Cramp F, Palmer S, . Exercise and self-management for people with chronic knee, hip or lower back pain: A cluster randomised controlled trial of clinical and cost-effectiveness. Study protocol. Physiotherapy (United Kingdom). 2013;99(4):352–357.
70 Willett M, Duda J, Gautrey C, Fenton S, Greig C, Rushton A. Effectiveness of behavioural change techniques in physiotherapy interventions to promote physical activity adherence in patients with hip and knee osteoarthritis: a systematic review protocol. BMJ Open. 2017;7(6):e015833.