# APPENDIX A SEARCH STRATEGIES

Database: MEDLINE (via Ovid MEDLINE ALL 1946 to July 26, 2021)

Search date: 7/27/2021

Search Set | Search Strategy | Results
#1 | (osteoarthritis/ AND (knee* OR hip* OR patella*).ti,ab.) OR exp Osteoarthritis, Hip/ or exp Osteoarthritis, Knee/ OR ((knee OR knees OR patella* OR hip OR hips) AND (osteoarthritis OR osteoarthritic OR arthrosis OR arthroses OR OA OR coxarthorsis OR coxarthroses)).ti,ab. OR ((knee* OR patella* OR hip OR hips) AND degenerative AND (arthritis OR arthritic OR joint OR joints)).ti,ab. | 55,259
#2 | exp low back pain/ OR exp sciatica/ OR (lumbago OR sciatica).ti,ab. | 30,239
#3 | ((back or low?back or spine or spinal or thoracic or vertebr* or intervertebr* or sciatic* or lumbar or lumbro* or lumbo*) adj3 (pain* or ache* or radiculopath* or polyradiculopath* or compress*)).ti,ab. | 80,218
#4 | (low or lower or lowback or sciatic* or ischia* or lumbo* or lumba* or sacroili* OR sacral).ti,ab. | 4,298,601
#5 | 3 AND 4 | 52,655
#6 | 1 OR 2 OR 5 | 117,475
#7 | (exp Rehabilitation/ AND physical.ti,ab.) OR exp Exercise/ OR exp Exercise Therapy/ OR exp Physical Fitness/ OR exp Physical Conditioning, Human/ OR exp Circuit-Based Exercise/ OR exp Endurance Training/ OR exp High-Intensity Interval Training/ OR exp Plyometric Exercise/ OR exp Resistance Training/ OR exp Physical Therapy Modalities/ OR exp Exercise Movement Techniques/ OR exp Tai Ji/ OR exp Yoga/ OR exp Hydrotherapy/ OR exp Musculoskeletal Manipulations/ OR exp Cognitive Behavioral Therapy/ OR exp “Acceptance and Commitment Therapy”/ OR exp Mindfulness/ OR exp Meditation/ OR exp Motivational Interviewing/ OR exp Wearable Electronic Devices/ OR exp Fitness Trackers/ OR exp Reminder Systems/ OR exp Peer Group/ OR exp Peer Influence/ OR exp Social Support/ OR exp Mentoring/ OR exp Text Messaging/ OR exp Mobile Applications/ OR (Physical ADJ rehab*).ti,ab. OR (Physical ADJ telerehab*).ti,ab. OR (Physical ADJ activit*).ti,ab. OR (Movement OR exercis* OR sport OR sports OR athletics OR athletic OR yoga OR pilates OR “Tai chi” OR “Tai ji” OR fitness OR plyometrics OR hydrotherapy OR “interval training” OR HIIT OR physiotherap* OR kinesiol* OR cycling OR spinning).ti,ab. OR ((circuit* OR strength* OR resistance* OR weight* OR aerobic* OR endurance) ADJ train*).ti,ab. OR (Physical ADJ therap*).ti,ab. OR ((musculoskeletal OR MSK) ADJ2 (therap* OR treat* OR therapeutic OR intervention* OR mobilization OR mobilisation)).ti,ab. OR ((behavior* OR behaviour* OR psychological OR mental) ADJ2 (therap* OR treat* OR therapeutic OR intervention* OR adaptation*)).ti,ab. OR CBT.ti,ab. OR ((acceptance OR commitment) ADJ2 (therap* OR treat* OR therapeutic OR intervention*)).ti,ab. OR (Motivation* ADJ2 interview*).ti,ab. OR (biopsychosocial OR bio?psycho?social OR counselling OR mindfulness OR meditation OR “Peer-to-peer”).ti,ab. OR ((peer OR peers OR social OR caregiver*) ADJ support*).ti,ab. OR (coach* OR mentor* OR counsel* OR boost* OR wearable* OR “fitness tracker” OR “fitness tracker” OR “activity tracker” OR “activity trackers” OR fitbit OR “apple watch”).ti,ab. OR (reminder* ADJ2 (system* OR messag* OR text* OR mail OR telephone OR phone)).ti,ab. OR (automated ADJ (messag* OR text* OR mail OR telephone OR phone)).ti,ab. OR (text?messag* OR email OR e?mail OR “electronic mail” OR “electronic message” OR “electronic messages”).ti,ab. OR (performance ADJ feedback).ti,ab. OR (Remote ADJ monitor*).ti,ab. OR (“mobile application” OR “mobile applications” OR “mobile apps”).ti,ab. | 1,498,833
#8 | 6 AND 7 | 24,101
#9 | exp Patient Compliance/ OR exp Medication Adherence/ OR exp Patient Participation/ OR “Patient Acceptance of Health Care”/ OR Treatment Refusal/ OR exp Motivation/ OR exp Self Efficacy/ OR exp Problem Solving/ OR exp Decision Making/ OR exp Choice Behavior/ OR (Adhere* OR adhering OR Complian* OR complying OR Cooperat*).ti,ab. OR ((change OR changes OR changing OR modify OR modifies OR modifying OR modification) ADJ (behavior* OR behaviour*)).ti,ab. OR (Motivat* OR incentiv* OR disincentiv* OR perceiv* OR perception* OR belief*).ti,ab. OR (Self ADJ efficacy).ti,ab. OR Self-efficacy.ti,ab. OR (Self ADJ monitoring).ti,ab. OR Self-monitoring.ti,ab. OR (Self ADJ talk).ti,ab. OR (Self-talk OR Attitude* OR Empower*).ti,ab. OR ((treat* OR therapy OR therapeutic) ADJ refus*).ti,ab. OR ((goal OR goals) ADJ setting).ti,ab. OR Goal-setting.ti,ab. OR (Action ADJ plan*).ti,ab. OR (Non?complian* OR Non?adheren* OR Attendance OR Non?attend* OR Encourag*).ti,ab. OR (patient ADJ3 participation).ti,ab. | 1,818,940
#10 | 8 AND 9 | 4,193
#11 | randomized controlled trial.pt. OR controlled clinical trial.pt. OR clinical trial.pt. OR randomized.ti,ab. OR randomised.ti,ab. OR randomization.ti,ab. OR randomisation.ti,ab. OR placebo.ti,ab. OR randomly.ti,ab. OR trial.ti,ab. OR groups.ti,ab. OR nonrandom.ti,ab. OR “non-random”.ti,ab. OR nonrandomized.ti,ab. OR “nonrandomized”.ti,ab. OR nonrandomised.ti,ab. OR “non-randomised”.ti,ab. OR quasi-experiment*.ti,ab. OR quazi-experiment*.ti,ab. OR quasiexperiment*.ti,ab. OR quaziexperiment*.ti,ab. OR quasirandom*.ti,ab. OR quazirandom*.ti,ab. OR quasi-random*.ti,ab. OR quazi-random*.ti,ab. OR quasi-control*.ti,ab. OR quazi-control*.ti,ab. OR quasicontrol*.ti,ab. OR quazicontrol*.ti,ab. OR ((controlled.ti,ab.) AND (trial.ti,ab. OR study.ti,ab.)) | 3,640,469
#12 | 10 AND 11 | 2,145
#13 | 12 NOT (exp animals/ not exp humans/) | 2,140
#14 | 13 NOT (case reports.pt OR editorial.pt OR letter.pt OR comment.pt) | 2,119

Database: Embase (via Elsevier)

Search date: 7/27/2021

Search Set | Search Strategy | Results
#1 | ‘knee osteoarthritis’/exp OR ‘hip osteoarthritis’/exp OR ((knee OR knees OR patella* OR hip OR hips) AND (osteoarthritis OR osteoarthritic OR arthrosis OR arthroses OR OA OR coxarthorsis OR coxarthroses)):ti,ab OR ((knee* OR patella* OR hip OR hips) AND degenerative AND (arthritis OR arthritic OR joint OR joints)):ti,ab | 79,989
#2 | ‘low back pain’/exp OR ‘sciatica’/exp OR (lumbago OR sciatica):ti,ab | 70,044
#3 | ((back or low?back or spine or spinal or thoracic or vertebr* or intervertebr* or sciatic* or lumbar or lumbro* or lumbo*) NEAR/3 (pain* or ache* or radiculopath* or polyradiculopath* or compress*)):ti,ab | 117,457
#4 | (low or lower or lowback or sciatic* or ischia* or lumbo* or lumba* or sacroili* OR sacral):ti,ab | 5,793,899
#5 | #3 AND #4 | 77,207
#6 | #1 OR# 2 OR #5 | 183,162
#7 | (‘rehabilitation’/exp AND physical:ti,ab) OR ‘exercise’/exp OR ‘kinesiotherapy’/exp OR ‘fitness’/exp OR ‘physiotherapy’/exp OR ‘Tai Chi’/exp OR ‘yoga’/exp OR ‘hydrotherapy’/exp OR ‘musculoskeletal manipulation’/exp OR ‘cognitive behavioral therapy’/exp OR ‘acceptance and commitment therapy’/exp OR ‘mindfulness’/exp OR ‘meditation’/exp OR ‘motivational interviewing’/exp OR ‘wearable computer’/exp OR ‘activity tracker’/exp OR ‘reminder system’/exp OR ‘peer group’/exp OR ‘peer pressure’/exp OR ‘social support’/exp OR ‘mentoring’/exp OR ‘text messaging’/exp OR ‘mobile application’/exp OR (Physical NEAR/1 rehab*):ti,ab OR (Physical NEAR/1 telerehab*):ti,ab OR (Physical NEAR/1 activit*):ti,ab OR (Movement OR exercis* OR sport OR sports OR athletics OR athletic OR yoga OR pilates OR ‘Tai chi’ OR ‘Tai ji’ OR fitness OR plyometrics OR hydrotherapy OR ‘interval training’ OR HIIT OR physiotherap* OR kinesiol* OR cycling OR spinning):ti,ab OR ((circuit* OR strength* OR resistance* OR weight* OR aerobic* OR endurance) NEAR/1 train*):ti,ab OR (Physical NEAR/1 therap*):ti,ab OR ((musculoskeletal OR MSK) NEAR/2 (therap* OR treat* OR therapeutic OR intervention* OR mobilization OR mobilisation)):ti,ab OR ((behavior* OR behaviour* OR psychological OR mental) NEAR/2 (therap* OR treat* OR therapeutic OR intervention* OR adaptation*)):ti,ab OR CBT:ti,ab OR ((acceptance OR commitment) NEAR/2 (therap* OR treat* OR therapeutic OR intervention*)):ti,ab OR (Motivation* NEAR/2 interview*):ti,ab OR (biopsychosocial OR bio?psycho?social OR counselling OR mindfulness OR meditation OR ‘Peer-to-peer’):ti,ab OR ((peer OR peers OR social OR caregiver*) NEAR/1 support*):ti,ab OR (coach* OR mentor* OR counsel* OR boost* OR wearable* OR ‘fitness tracker’ OR ‘fitness tracker’ OR ‘activity tracker’ OR ‘activity trackers’ OR fitbit OR ‘apple watch’):ti,ab OR (reminder* NEAR/2 (system* OR messag* OR text* OR mail OR telephone OR phone)):ti,ab OR (automated NEAR/1 (messag* OR text* OR mail OR telephone OR phone)):ti,ab OR (text?messag* OR email OR e?mail OR ‘electronic mail’ OR ‘electronic message’ OR ‘electronic messages’):ti,ab OR (performance NEAR/1 feedback):ti,ab OR (Remote NEAR/1 monitor*):ti,ab OR (‘mobile application’ OR ‘mobile applications’ OR ‘mobile apps’):ti,ab | 1,937,779
#8 | #6 AND #7 | 37,245
#9 | ‘patient compliance’/exp OR ‘medication compliance’/exp OR ‘patient participation’/exp OR ‘patient attitude’/exp OR ‘treatment refusal’/exp OR ‘motivation’/exp OR ‘self concept’/exp OR ‘problem solving’/exp OR ‘decision making’/exp OR (Adhere* OR adhering OR Complian* OR complying OR Cooperat*):ti,ab OR ((change OR changes OR changing OR modify OR modifies OR modifying OR modification) NEAR/1 (behavior* OR behaviour*)):ti,ab OR (Motivat* OR incentiv* OR disincentiv* OR perceiv* OR perception* OR belief*):ti,ab OR (Self NEAR/1 efficacy):ti,ab OR Self-efficacy:ti,ab OR (Self NEAR/1 monitoring):ti,ab OR Self-monitoring:ti,ab OR (Self NEAR/1 talk):ti,ab OR (Self-talk OR Attitude* OR Empower*):ti,ab OR ((treat* OR therapy OR therapeutic) NEAR/1 refus*):ti,ab OR ((goal OR goals) NEAR/1 setting):ti,ab OR Goal-setting:ti,ab OR (Action NEAR/1 plan*):ti,ab OR (Non?complian* OR Non?adheren* OR Attendance OR Non?attend* OR Encourag*):ti,ab OR (patient NEAR/3 participation):ti,ab | 2,749,149
#10 | #8 AND #9 | 8,078
#11 | ‘crossover procedure’/exp OR ‘randomized controlled trial’/exp OR ‘controlled clinical trial’/exp OR ‘single blind procedure’/exp OR ‘double blind procedure’/exp OR ‘crossover procedure’:de OR ‘double-blind procedure’:de OR ‘randomized controlled trial’:de OR ‘single-blind procedure’:de OR (random* OR factorial* OR crossover* OR cross NEXT/1 over* OR placebo* OR doubl* NEAR/1 blind* OR singl* NEAR/1 blind* OR assign* OR allocat* OR volunteer*):ti,ab OR placebo:ti,ab OR groups:ti,ab OR nonrandom:ti,ab OR non?random:ti,ab OR nonrandomized:ti,ab OR non?randomized:ti,ab OR nonrandomised:ti,ab OR non?randomised:ti,ab OR quasi?experiment*:ti,ab OR quazi?experiment*:ti,ab OR quasiexperiment*:ti,ab OR quaziexperiment*:ti,ab OR quasirandom*:ti,ab OR quazirandom*:ti,ab OR quasi?random*:ti,ab OR quazi?random*:ti,ab OR quasi?control*:ti,ab OR quazi?control*:ti,ab OR quasicontrol*:ti,ab OR quazicontrol*:ti,ab OR ((controlled:ti,ab) AND (trial:ti,ab OR study:ti,ab)) | 5,425,748
#12 | #10 AND #11 | 3,771
#13 | #12 AND [humans]/lim | 3,676
#14 | #13 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR [editorial]/lim OR ‘letter’/exp OR [letter]/lim OR ‘note’/exp OR [note]/lim OR [conference abstract]/lim OR ‘conference abstract’/exp OR ‘conference abstract’/it) | 2,655

Database: CINAHL Complete (via EBSCO)

Search date: 7/27/2021

Search Set | Search Strategy | Results
#1 | ((MH osteoarthritis) AND ((TI knee* OR AB knee*) OR (TI hip* OR AB hip*) OR (TI patella* OR AB patella*))) OR (MH “Osteoarthritis, Hip”) OR (MH “Osteoarthritis, Knee”) OR (((TI knee OR AB knee) OR (TI knees OR AB knees) OR (TI patella* OR AB patella*) OR (TI hip OR AB hip) OR (TI hips OR AB hips)) AND ((TI osteoarthritis OR AB osteoarthritis) OR (TI osteoarthritic OR AB osteoarthritic) OR (TI arthrosis OR AB arthrosis) OR (TI arthroses OR AB arthroses) OR (TI OA OR AB OA) OR (TI coxarthorsis OR AB coxarthorsis) OR (TI coxarthroses OR AB coxarthroses))) OR (((TI knee* OR AB knee*) OR (TI patella* OR AB patella*) OR (TI hip OR AB hip) OR (TI hips OR AB hips)) AND (TI degenerative OR AB degenerative) AND ((TI arthritis OR AB arthritis) OR (TI arthritic OR AB arthritic) OR (TI joint OR AB joint) OR (TI joints OR AB joints))) | 26,315
#2 | (MH “Low Back Pain”) OR (MH “sciatica”) OR ((TI lumbago OR AB lumbago) OR (TI sciatica OR AB sciatica)) | 22,894
#3 | (((TI back OR AB back) OR (TI low#back OR AB low#back) OR (TI spine OR AB spine) OR (TI spinal OR AB spinal) OR (TI thoracic OR AB thoracic) OR (TI vertebr* OR AB vertebr*) OR (TI intervertebr* OR AB intervertebr*) OR (TI sciatic* OR AB sciatic*) OR (TI lumbar OR AB lumbar) OR (TI lumbro* OR AB lumbro*) OR (TI lumbo* OR AB lumbo*)) N3 ((TI pain* OR AB pain*) OR (TI ache* OR AB ache*) OR (TI radiculopath* OR AB radiculopath*) OR (TI polyradiculopath* OR AB polyradiculopath*) OR (TI compress* OR AB compress*))) | 39,563
#4 | ((TI low OR AB low) OR (TI lower OR AB lower) OR (TI lowback OR AB lowback) OR (TI sciatic* OR AB sciatic*) OR (TI ischia* OR AB ischia*) OR (TI lumbo* OR AB lumbo*) OR (TI lumba* OR AB lumba*) OR (TI sacroili* OR AB sacroili*) OR (TI sacral OR AB sacral)) | 760,111
#5 | S3 AND S4 | 27,382
#6 | S1 OR S2 OR S5 | 60,510
#7 | ((MH “Rehabilitation+”) AND (TI physical OR AB physical)) OR (MH “Exercise+”) OR (MH “Therapeutic Exercise+” OR (MH “Physical Fitness+”) OR (MH “Physical Therapy+”) OR (MH “Resistance Training”) OR (MH “Yoga+”) OR (MH “Tai Chi”) OR (MH “Meditation”) OR (MH “Mental Healing”) OR (MH “Hydrotherapy”) OR (MH “Applied Kinesiology”) OR (MH “Manual Therapy”) OR (MH “Cognitive Therapy+”) OR (MH “Acceptance and Commitment Therapy”) OR (MH “Mindfulness”) OR (MH “Motivational Interviewing”) OR (MH “Wearable Sensors+”) OR (MH “Fitness Trackers”) OR (MH “Reminder Systems”) OR (MH “Peer Group”) OR (MH “Peer Pressure”) OR (MH “Support, Psychosocial”) OR (MH “Mentorship”) OR (MH “Text Messaging+”) OR (MH “Mobile Applications”) OR ((TI Physical OR AB Physical) W1 (TI rehab* OR AB rehab*)) OR ((TI Physical OR AB Physical) W1 (TI telerehab* OR AB telerehab*)) OR ((TI Physical OR AB Physical) W1 (TI activit* OR AB activit*)) OR ((TI Movement OR AB Movement) OR (TI exercis* OR AB exercis*) OR (TI sport OR AB sport) OR (TI sports OR AB sports) OR (TI athletics OR AB athletics) OR (TI athletic OR AB athletic) OR (TI yoga OR AB yoga) OR (TI pilates OR AB pilates) OR (TI “Tai chi” OR AB “Tai chi”) OR (TI “Tai ji” OR AB “Tai ji”) OR (TI fitness OR AB fitness) OR (TI plyometrics OR AB plyometrics) OR (TI hydrotherapy OR AB hydrotherapy) OR (TI “interval training” OR AB “interval training”) OR (TI HIIT OR AB HIIT) OR (TI physiotherap* OR AB physiotherap*) OR (TI kinesiol* OR AB kinesiol*) OR (TI cycling OR AB cycling) OR (TI spinning OR AB spinning)) OR (((TI circuit* OR AB circuit*) OR (TI strength* OR AB strength*) OR (TI resistance* OR AB resistance*) OR (TI weight* OR AB weight*) OR (TI aerobic* OR AB aerobic*) OR (TI endurance OR AB endurance)) W1 (TI train* OR AB train*)) OR ((TI Physical OR AB Physical) W1 (TI therap* OR AB therap*)) OR (((TI musculoskeletal OR AB musculoskeletal) OR (TI MSK OR AB MSK)) N2 ((TI therap* OR AB therap*) OR (TI treat* OR AB treat*) OR (TI therapeutic OR AB therapeutic) OR (TI intervention* OR AB intervention*) OR (TI mobilization OR AB mobilization) OR (TI mobilisation OR AB mobilisation))) OR (((TI behavior* OR AB behavior*) OR (TI behaviour* OR AB behaviour*) OR (TI psychological OR AB psychological) OR (TI mental OR AB mental)) N2 ((TI therap* OR AB therap*) OR (TI treat* OR AB treat*) OR (TI therapeutic OR AB therapeutic) OR (TI intervention* OR AB intervention*) OR (TI adaptation* OR AB adaptation*))) OR (TI CBT OR AB CBT) OR (((TI acceptance OR AB acceptance) OR (TI commitment OR AB commitment)) N2 ((TI therap* OR AB therap*) OR (TI treat* OR AB treat*) OR (TI therapeutic OR AB therapeutic) OR (TI intervention* OR AB intervention*))) OR ((TI Motivation* OR AB Motivation*) N2 (TI interview* OR AB interview*)) OR ((TI biopsychosocial OR AB biopsychosocial) OR (TI bio#psycho#social OR AB bio#psycho#social) OR (TI counselling OR AB counselling) OR (TI mindfulness OR AB mindfulness) OR (TI meditation OR AB meditation) OR (TI Peer-to-peer OR AB Peer-to-peer)) OR (((TI peer OR AB peer) OR (TI peers OR AB peers) OR (TI social OR AB social) OR (TI caregiver* OR AB caregiver*)) W1 (TI support* OR AB support*)) OR ((TI coach* OR AB coach*) OR (TI mentor* OR AB mentor*) OR (TI counsel* OR AB counsel*) OR (TI boost* OR AB boost*) OR (TI wearable* OR AB wearable*) OR (TI “fitness tracker” OR AB “fitness tracker”) OR (TI “fitness tracker” OR AB “fitness tracker”) OR (TI “activity tracker” OR AB “activity tracker”) OR (TI “activity trackers” OR AB “activity trackers”) OR (TI fitbit OR AB fitbit) OR (TI “apple watch” OR AB “apple watch”)) OR ((TI reminder* OR AB reminder*) N2 ((TI system* OR AB system*) OR (TI messag* OR AB messag*) OR (TI text* OR AB text*) OR (TI mail OR AB mail) OR (TI telephone OR AB telephone) OR (TI phone OR AB phone))) OR ((TI automated OR AB automated) W1 ((TI messag* OR AB messag*) OR (TI text* OR AB text*) OR (TI mail OR AB mail) OR (TI telephone OR AB telephone) OR (TI phone OR AB phone))) OR ((TI text#messag* OR AB text#messag*) OR (TI email OR AB email) OR (TI e#mail OR AB e#mail) OR (TI “electronic mail” OR AB “electronic mail”) OR (TI “electronic message” OR AB “electronic message”) OR (TI “electronic messages” OR AB “electronic messages”)) OR ((TI performance OR AB performance) W1 (TI feedback OR AB feedback)) OR ((TI Remote OR AB Remote) W1 (TI monitor* OR AB monitor*)) OR ((TI “mobile application” OR AB “mobile application”) OR (TI “mobile applications” OR AB “mobile applications”) OR (TI “mobile apps” OR AB “mobile apps”)) | 773,686
#8 | S6 AND S7 | 17,992
#9 | (MH “Patient Compliance+”) OR (MH “Medication Compliance”) OR (MH “Consumer Participation”) OR (MH “Treatment Refusal”) OR (MH “Motivation+”) OR (MH “Self Efficacy”) OR (MH “Problem Solving+”) OR (MH “Decision Making+”) OR ((TI Adhere* OR AB Adhere*) OR (TI adhering OR AB adhering) OR (TI Complian* OR AB Complian*) OR (TI complying OR AB complying) OR (TI Cooperat* OR AB Cooperat*)) OR (((TI change OR AB change) OR (TI changes OR AB changes) OR (TI changing OR AB changing) OR (TI modify OR AB modify) OR (TI modifies OR AB modifies) OR (TI modifying OR AB modifying) OR (TI modification OR AB modification)) W1 ((TI behavior* OR AB behavior*) OR (TI behaviour* OR AB behaviour*))) OR ((TI Motivat* OR AB Motivat*) OR (TI incentiv* OR AB incentiv*) OR (TI disincentiv* OR AB disincentiv*) OR (TI perceiv* OR AB perceiv*) OR (TI perception* OR AB perception*) OR (TI belief* OR AB belief*)) OR ((TI Self OR AB Self) W1 (TI efficacy OR AB efficacy)) OR (TI Self-efficacy OR AB Self-efficacy) OR ((TI Self OR AB Self) W1 (TI monitoring OR AB monitoring)) OR (TI Self-monitoring OR AB Selfmonitoring) OR ((TI Self OR AB Self) W1 (TI talk OR AB talk)) OR ((TI Self-talk OR AB Self-talk) OR (TI Attitude* OR AB Attitude*) OR (TI Empower* OR AB Empower*)) OR (((TI treat* OR AB treat*) OR (TI therapy OR AB therapy) OR (TI therapeutic OR AB therapeutic)) W1 (TI refus* OR AB refus*)) OR (((TI goal OR AB goal) OR (TI goals OR AB goals)) W1 (TI setting OR AB setting)) OR (TI Goal-setting OR AB Goal-setting) OR ((TI Action OR AB Action) W1 (TI plan* OR AB plan*)) OR ((TI Non#complian* OR AB Non#complian*) OR (TI Non#adheren* OR AB Non#adheren*) OR (TI Attendance OR AB Attendance) OR (TI Non#attend* OR AB Non#attend*) OR (TI Encourag* OR AB Encourag*)) OR ((TI patient OR AB patient) N3 (TI participation OR AB participation)) | 792,963
#10 | S8 AND S9 | 3,188
#11 | (ZT “randomized controlled trial”) OR (MH “Randomized Controlled Trials”) OR TI (“randomized controlled trial” OR “controlled clinical trial” OR randomized OR randomised OR randomization OR randomisation OR placebo OR randomly OR trial OR trials OR groups OR “single blind” OR “single blinded” OR “double blind” OR “double-blinded OR nonrandom* OR non-random* OR quasiexperiment* OR quasi-experiment* OR quaziexperiment* OR quazi-experiment* OR quasirandom* OR quasi-random* OR quazirandom* OR quazi-random* OR quasicontrol* OR quasi-control* OR quazicontrol* OR quazi-control*) OR AB (“randomized controlled trial” OR “controlled clinical trial” OR randomized OR randomised OR randomization OR randomisation OR placebo OR randomly OR trial OR trials OR groups OR “single blind” OR “single blinded” OR “double blind” OR “double-blinded OR nonrandom* OR non-random* OR quasiexperiment* OR quasi-experiment* OR quaziexperiment* OR quazi-experiment* OR quasirandom* OR quasi-random* OR quazirandom* OR quazi-random* OR quasicontrol* OR quasi-control* OR quazicontrol* OR quazi-control*) | 300,658
#12 | S10 AND S11 | 758
#13 | S12 NOT PT ( Abstract OR Book OR Book Chapter OR Book Review OR Case Study OR Commentary OR Editorial OR Letter OR Masters Thesis OR Pamphlet OR Pamphlet Chapter OR Poetry ) | 738