# ABBREVIATIONS TABLE

Abbreviation: Definition
BCT: Behavior change technique
CBT: Cognitive behavior therapy
CI: Confidence interval
COE: Certainty of evidence
COM-B: Capability, opportunity, and motivation
ESP: Evidence Synthesis Program
GRADE: Grading of Recommendations Assessment, Development, and Evaluation
KOOS: Knee and Osteoarthritis Outcome Score
KQ: Key question
LBP: Low back pain
NRS: Numeric rating scale
OA: Osteoarthritis
OECD: Organisation for Economic Co-operation and Development
OR: Odds ratio
PRESS: Peer Review of Electronic Search Strategies
PRISMA: Preferred Reporting Items for Systematic Reviews and Meta Analyses
PT: Physical therapy
ROB: Risk of bias
RR&D: Rehabilitation Research and Development
SD: Standard deviation
SEE: Self-Efficacy for Exercise Scale
SMD: Standardized mean difference
VHA: Veterans Health Administration
WOMAC: Western Ontario and McMaster Universities Osteoarthritis Index