# Evidence Brief: Proton Beam Therapy for Treatment of Localized Prostate Cancer

## PREFACE

The VA Evidence Synthesis Program (ESP) was established in 2007 to provide timely and accurate syntheses of targeted health care topics of importance to clinicians, managers, and policymakers as they work to improve the health and health care of Veterans. These reports help:

- Develop clinical policies informed by evidence;
- Implement effective services to improve patient outcomes and to support VA clinical practice guidelines and performance measures; and
- Set the direction for future research to address gaps in clinical knowledge.

The program comprises four ESP Centers across the US and a Coordinating Center located in Portland, Oregon. Center Directors are VA clinicians and recognized leaders in the field of evidence synthesis with close ties to the AHRQ Evidence-based Practice Center Program. The Coordinating Center was created to manage program operations, ensure methodological consistency and quality of products, interface with stakeholders, and address urgent evidence needs. To ensure responsiveness to the needs of decision-makers, the program is governed by a Steering Committee composed of health system leadership and researchers. The program solicits nominations for review topics several times a year via the program website (https://www.hsrd.research.va.gov/publications/esp/TopicNomination.cfm).

The present report was developed in response to a request from the VHA National Radiation Oncology Program (NROP). The scope was further developed with input from Operational Partners (below) and the ESP Coordinating Center review team.

## ACKNOWLEDGMENTS

The authors are grateful to Kathryn Vela, MLIS for literature searching, Mark Helfand, MD, MPH, MS for review of the draft and final report, and the following individuals for their contributions to this project:

### Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Maria Kelly, MD, FACR, FASTRO, FAAWR
  Executive Director
  NROP

### Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix E in Supplemental Materials for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained.

The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.

## EXECUTIVE SUMMARY

#### Background

The VA Evidence Synthesis Program (ESP) Coordinating Center is responding to a request from the VHA National Radiation Oncology Program (NROP) for an Evidence Brief updating a 2015 ESP evidence review on the benefits and harms of proton beam therapy (PBT) for localized prostate cancer. Findings from this report will be used to inform NROP policies on the provision of PBT for the treatment of prostate cancer.

#### Methods

To identify studies, we searched MEDLINE, Cochrane Database of Systematic Reviews, Cochrane Central Register of Controlled Trials, and other sources up to February 2022. We used prespecified criteria for study selection, data abstraction, and rating internal validity and strength of the evidence. See the Methods section and our PROSPERO protocol for full details of our methodology.

Key Findings

- Comparative evidence on gastrointestinal (GI) and genitourinary (GU) toxicity after treatment of localized prostate cancer with proton beam therapy (PBT) or intensity-modulated radiation therapy (IMRT) is low strength.
- Risk of early GI and GU toxicity is possibly lower after treatment with PBT compared with IMRT (RR_GI_ = 0.76, 95% CI [0.39, 1.50]; RR_GU_ = 0.65, 95% CI [0.28, 1.34]).
- In the first year after PBT or IMRT, GI toxicity risk may not differ between modalities, while risk of GU toxicity is possibly lower after treatment with PBT compared with IMRT (RR_GI_ = 1.08, 95% CI [0.68, 1.95]; RR_GU_ = 0.82, 95% CI [0.57, 1.29]).
- Low-strength evidence suggests that PBT and brachytherapy confer similar overall survival rates, and that GI and GU toxicity rates are similar for hypofractionation and conventional dosing.
- Evidence is insufficient to determine whether second cancers are less likely after PBT compared with IMRT, or whether PBT has advantages over IMRT for the treatment of relapsed prostate cancer initially treated with radical prostatectomy.
- Underway RCTs could provide important additions to the evidence base on the comparative effectiveness of PBT.

Prostate cancer accounts for more than 25% of new cancer cases diagnosed in men. The most commonly used strategies for managing prostate cancer are surveillance without initial active treatment, treatment with surgical resection (radical prostatectomy), or radiation therapy. Because active treatments destroy cancer cells but can damage surrounding nerves, the bladder, the urethra, or the rectum, it is important that patients and providers understand the benefits and potential harms of available treatment and management options.

Radiation therapy for prostate cancer can be categorized into external beam therapy using high-intensity photons, brachytherapy, and charged particle therapy (usually using proton beams). In the last 2 decades, the use of brachytherapy has declined in the US, while the use of proton beam therapy (PBT) has increased. Evidence from direct comparisons of alternative modalities has high potential value for guiding treatment choice. A 2015 review conducted by the VA Evidence Synthesis Program (ESP) on PBT concluded that there was not enough evidence on its effectiveness to determine whether it was better, worse, or equivalent to conventional therapies for prostate cancer. There continues to be considerable demand for PBT, however, and this review provides an up-to-date synthesis of evidence on benefits and harms of PBT compared with other radiation modalities.

Forty-seven studies (in 52 publications) reported outcomes of treatment with PBT and were included in this updated review. A summary of available evidence is provided in the ES Table.

Ten included studies compared PBT to contemporary forms of photon-based radiation therapy (eg, intensity-modulated radiation therapy [IMRT]) and were rated as having a low risk of bias. Evidence from 3 studies comparing PBT and IMRT for initial treatment of newly diagnosed prostate cancer suggests that risk of early gastrointestinal (GI) and genitourinary (GU) toxicity is possibly lower after PBT compared with IMRT. Results of 4 studies suggest that in the first year after PBT or IMRT, GI toxicity risk may not differ between modalities, while GU toxicity risk is possibly lower after treatment with PBT compared with IMRT. No pooled findings on GI or GU toxicity risk were statistically significant, and evidence on both outcomes was rated as low strength. Single studies reported on quality of life, second malignancy, and overall survival, and it is unclear whether PBT and IMRT differ in these outcomes. Two studies observed similar overall survival after PBT or brachytherapy.

ES Table Summary of Evidence

Outcome | Evidence | Findings
PBT vs IMRT for Initial Therapy of Prostate Cancer
3-month GI Toxicity | 3 cohort studies^1–3^ | Low SOE: Risk of early GI toxicity is possibly lower after PBT compared with IMRT (RR_Mean_ = 0.76, 95% CI [0.39, 1.50]).
3-month GU Toxicity | 3 cohort studies^1–3^ | Low SOE: Risk of early GU toxicity is possibly lower after PBT compared with IMRT (RR_Mean_ = 0.65, 95% CI [0.28, 1.34]).
1-year GI Toxicity | 4 cohort studies^1,2,4,5^ | Low SOE: Risk of GI toxicity may not differ 1 year after PBT or IMRT (RR_Mean_ = 1.08, 95% CI [0.68, 1.95]).
1-year GU Toxicity | 4 cohort studies^1,2,4,5^ | Low SOE: Risk of GU toxicity is possibly lower 1 year after PBT compared with IMRT (RR_Mean_ = 0.82, 95% CI [0.57, 1.29]).
Second Malignancy | 1 cohort study^6^ | Insufficient SOE: It is unclear whether PBT and IMRT differ in risk of second malignancy after treatment.
Quality of Life | 1 cohort study^1^ | Insufficient SOE: It is unclear whether PBT and IMRT differ in quality-of-life scores following treatment.
Overall Survival | 1 cohort study^7^ | Insufficient SOE: It is unclear whether PBT and IMRT differ in survival following treatment.
PBT vs Brachytherapy for Initial Therapy of Prostate Cancer
Overall Survival | 2 cohort studies^7,8^ | Low SOE: PBT and brachytherapy confer similar impacts on overall survival.
Rates of Toxicity | 0 studies | Insufficient SOE: It is unclear whether PBT and brachytherapy differ in toxicity rates (including GI and GU toxicities and second cancer incidence) after treatment.
Effect of Patient Factors on the Results of Treatment with PBT
Effect of Patient Race | 2 cohort studies^9,10^ | Low SOE: Black and white patients had similar GU and GI toxicity rates.
Anticoagulant Use | 3 cohort studies^11–13^ | Low SOE: Patients who used anticoagulant medications had a higher rate of rectal bleeding.
Prior Prostate Surgery | 2 cohort studies^14,15^ | Low SOE: Patients who had prior prostate surgery had higher rates of GU toxicity.
Baseline Cancer Risk Score | 13 cohort studies^9,10,12,15–26^ | Low SOE: Patients with worse baseline risk assessments experienced higher rates of cancer recurrence over time.
Impact of Technical Aspects of PBT Delivery
Hypofractionation Effect on Toxicity Rates | 2 RCTs and 2 cohort studies^27–31^ | Low SOE: Patients treated with hypofractionation had similar rates of GU and GI toxicity as patients who were treated with conventional dosing schedules.
Hypofractionation Effect on Cancer Relapse | 1 RCT^27^ | Insufficient SOE: It is unclear whether patients treated with hypofractionation have different rates of cancer recurrence than patients treated with conventional dosing schedules.
PBT vs IMRT for Therapy of Relapsed Prostate Cancer
Disease Progression Following Treatment | 1 cohort study^32^ | Insufficient SOE: It is unclear whether PBT has advantages over IMRT for the treatment of relapsed prostate cancer following original initial therapy with radical prostatectomy.

Abbreviations. CI=confidence interval; Freq.=Frequentist; GI=gastrointestinal; GU=genitourinary; IMRT=intensity-modulated radiation therapy; PBT=proton beam therapy; RCT=randomized control trial; RR=risk ratio; SOE=strength of evidence.

The remaining studies on the effectiveness of PBT provided low- or insufficient-strength evidence on the role of patient and technical factors in PBT benefits and harms. Several patient factors were associated with a higher incidence of GI or GU toxicity (older age, history of prior prostate surgery, use of anticoagulation medications) or disease progression (baseline cancer risk score). Black and white patients appear to experience similar GI and GU toxicity risk. Studies on hypofractionation (which reduces the total number of PBT treatment sessions and overall duration of treatment) report similar GI and GU toxicity rates for hypofractionation and conventional dosing schedules. Available evidence is insufficient to reach conclusions about 2 other aspects of PBT delivery: total radiation dose and use of pencil beam scanning.

Although additional studies have been published on PBT in the last 7 years, evidence on its comparative benefits and harms remains low or insufficient strength. More studies are needed to address evidence gaps, including cancer recurrence rates following PBT and IMRT, toxicity among comparable patients receiving PBT or brachytherapy, and use of PBT in cases of prostate cancer relapse after initial treatment with another therapy. Several controlled clinical trials are currently underway and could address some open questions, but their results are likely years away. Currently available evidence may be useful in patient-provider decisions about the treatment of localized prostate cancer, yet it also reveals important uncertainties that are necessary to consider in the complex and nuanced choice of treatment modality.

## INTRODUCTION

### PURPOSE

The Evidence Synthesis Program (ESP) Coordinating Center is responding to a request from the VHA National Radiation Oncology Program (NROP) for an Evidence Brief updating a 2015 ESP evidence review on the benefits and harms of proton beam therapy (PBT) for localized prostate cancer. Findings from this report will be used to inform NROP policies on the provision of PBT for the treatment of prostate cancer.

### BACKGROUND

About 1 in every 8 American men will be diagnosed with prostate cancer.^33^ Based on data from the National Cancer Institute Surveillance, Epidemiology, and End Results (SEER) Program, an estimated 248,530 new cases of prostate cancer were diagnosed in 2021, comprising about 13% of all newly diagnosed cancers in the US. Among men, prostate cancer accounts for more than 25% of new cancer diagnoses, and non-Hispanic Black men and older men are at highest risk.^33^

Prostate cancer screening is widespread in the US and most cases are discovered while the cancer is still localized.^34^ Some men have relatively small and nonaggressive tumors for which surveillance without initial active treatment is appropriate. For men who elect initial treatment, the most commonly used modalities are surgical resection (ie, radical prostatectomy) or radiation therapy. Radiation therapies for prostate cancer can be grouped into 3 general categories. The most frequently used radiation therapy delivers high-energy photons via external beams. Brachytherapy is an alternative approach that imbeds radiation sources directly into the prostate that deliver photon radiation over several months. Finally, PBT targets the prostate with a beam of protons generated by a cyclotron. Over the last 2 decades, use of PBT has increased in the US, while use of brachytherapy has declined.^35^

Active treatment approaches for localized prostate cancer destroy cancer cells but can damage surrounding nerves, the bladder, the urethra, or the rectum, leading to undesirable symptoms of varying duration. As treatment strategies for localized prostate cancer have evolved over recent decades, limiting damage to healthy tissues surrounding the prostate has become a major focus. For instance, technological advances have led to widespread adoption of intensity-modulated radiation therapy (IMRT), a type of external beam photon therapy. IMRT is intended to reduce clinical complications of conventional external beam photon therapy by altering the direction of the external beam and regulating the intensity of the radiation delivered to the prostate and nearby tissues. As of 2011, IMRT was used in 70% of patients receiving radiation therapy for prostate cancer, while PBT was used in only 3%.^35^

Research has also explored whether the overall duration of external beam radiation therapy using photons or protons could be shortened through dosage schedules known as hypofractionation. Conventional external beam radiation therapy for prostate cancer typically has been performed with a few dozen treatment sessions spread over a period of 1-2 months. Hypofractionation shortens the period of treatment by delivering larger doses of radiation in each session over fewer total sessions. Additionally, newer approaches to photon-based radiation therapy such as stereotactic ablative body radiation have become available in the US, but the clinical evidence base for these new modalities is still developing.^36^

Men with newly diagnosed prostate cancer who pursue radiation therapy are faced with many different treatment choices. Although evidence derived from direct comparisons of alternative modalities is optimal for guiding this choice, a 2015 ESP review^37^ on PBT concluded that there was not enough evidence on its effectiveness to determine whether it was better, worse, or equivalent to conventional therapies for prostate cancer. There continues to be considerable demand for PBT, however, and this review provides an up-to-date synthesis of evidence on benefits and harms of PBT compared with other radiation modalities, as well as evidence on whether treatment benefits and harms differ for men with certain clinical characteristics.

## METHODS

### PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022310783).

### KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 What are the benefits and harms of PBT compared to conventional external beam radiation therapy or brachytherapy for the treatment of early stage localized prostate cancer?
KQ1a Do benefits or harms of PBT vary according to fractionation schedules, beam targeting modality (passive scattering vs pencil beam scanning), or patient characteristics (eg, symptom score, prostate size)?
KQ2 For patients with progression or recurrence of cancer in the prostate who were not previously treated with radiation therapy, what are the benefits and harms of PBT compared to conventional forms of radiation therapy?

### ANALYTIC FRAMEWORK

The analytic framework shown in Figure 1 provides a conceptual overview of this review. The population of interest was men who have biopsy-confirmed adenocarcinoma of the prostate. Eligible outcomes were survival, impact of the cancer on quality of life, and treatment harms (Key Questions 1 and 2). The clinical literature also frequently refers to intermediate outcomes related to signs of tumor progression (including tumor size and the level of prostate specific antigen [PSA] in the blood). We examined these intermediate outcomes because of a plausible association of these measures with changes in eligible patient-relevant outcomes. Whether benefits and/or harms of the intervention differ by patient characteristics (eg, patient demographics, comorbidities, disease severity) or treatment protocol (eg, number of sessions, technical aspects of the delivery of the radiation dose) was also of interest (Key Question 1a).

Figure 1 Analytic Framework

Abbreviations. KQ=key question.

### ELIGIBILITY CRITERIA

The review included studies that met the following criteria:

Population: | Adults with localized prostate cancer
Intervention: | Proton beam irradiation therapy
Comparators: | Radiotherapy using X-ray-based external beam modalities or brachytherapy
Outcomes: | - Benefits: Survival, quality of life, functional capacity, local tumor control, delivery of planned radiation regimens; - Harms: Gastrointestinal (GI) and genitourinary (GU) symptoms, second malignancies, soft tissue damage
Timing: | Any
Setting: | Any
Study Design: | Any, but we may prioritize studies using a best-evidence approach to accommodate project timeline

### DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, Ovid CENTRAL, and ClinicalTrials.gov, as well as the AHRQ and Cochrane Databases of Systematic Reviews through February 2022 using terms for proton beam and prostate cancer (see Appendix A in Supplemental Materials for complete search strategies). Formal Requests for Scientific Information were sent to manufacturers of proton therapy systems (see Appendix B for list of proton therapy centers). Additional citations were identified from hand-searching reference lists and consultation with content experts. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. Titles, abstracts, and full-text articles were reviewed by 1 investigator and checked by another. All disagreements were resolved by consensus or discussion with a third reviewer.

Key Questions 1 and 2 are comparative effectiveness questions, so all studies judged to be potentially relevant compared outcomes in 2 or more patient groups (as defined by the type of radiation therapy administered). Studies with comparative data were included in the review if patients in the comparison condition received IMRT or brachytherapy and patients in all conditions were treated for similar durations. Studies comparing PBT to older modalities for delivery of external beam proton therapy were excluded. Studies that examined only PBT (ie, without a comparator group receiving another type of radiation therapy) and stratified patients into subgroups defined by patient characteristics or difference in the dosage, schedule, or delivery method of PBT were considered eligible to address Key Question 1a.

### DATA ABSTRACTION AND ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. The internal validity (risk of bias) of each included comparative study was rated using the ROBINS-I tool for observational studies.^38^ For studies with observational designs, this tool assesses the risk of bias attributable to confounding. For studies that were not controlled trials but reported data about non-PBT comparator groups, we examined what methodologies were used to improve the comparability of patient groups, such as one-to-one case matching, matching based on propensity scores, or case weighting using inverse probability weighting. All data abstraction and internal validity ratings were first completed by 1 investigator and then checked by 2 others; disagreements were resolved by discussion among the 3 investigators (DHH, JKA, NJP).

We graded the strength of the evidence (SOE) for outcomes based on the AHRQ Methods Guide for Comparative Effectiveness Reviews.^39^ This approach provided a rating of confidence in reported findings based on trial methodology (design, quality, and risk of bias), consistency (whether effects are in the same direction and have a consistent magnitude), and directness (whether assessed outcomes are clinically important to patients and providers). When information on precision of findings (eg, confidence intervals) was available, certainty of evidence was also evaluated. For this review, we applied the following general algorithm: high strength evidence consisted of multiple, large controlled trials with low risk of bias, consistent and precise findings, and clinically relevant outcomes; moderate strength evidence consisted of multiple trials or well conducted comparative cohort studies with low risk of bias, consistent and precise findings, and clinically relevant outcomes; low strength evidence consisted of a single study, or multiple small studies, with varying risk of bias, inconsistent or imprecise findings, and/or outcomes with limited clinical relevance; and insufficient evidence consisted of a single study with moderate or high risk of bias, or no available studies.

### SYNTHESIS

Studies were categorized by the characteristics of the patient populations, the types of treatments compared, and the types of clinical outcomes considered. When there were 2 or more studies that examined the same treatment comparisons in similar patient populations and with comparable outcome timing, study results were pooled using meta-analysis. Because the amount of between-study variation in true effects (ie, heterogeneity) can be difficult to estimate in meta-analyses of few studies, we employed Bayesian random-effects models to fully account for imprecision in heterogeneity estimates.^40^ Models were fitted with limited prior information: For mean effects, a Normal prior with a mean of 0 and standard deviation of 4 was specified.^41^ Heterogeneity magnitude was estimated with a half-Normal prior with a scale of 0.5, reflecting possible moderate to high heterogeneity, and sensitivity analyses were conducted at a scale of 1.0 (allowing extreme heterogeneity).^41–44^

Meta-analysis results are presented with 95% highest posterior density credible intervals (CIs), which were used to evaluate statistical significance (ie, whether there was an at least 95% probability that a mean effect estimate differed from 1, or no difference between treatment groups). To assess variation in effects across studies, we report 95% prediction intervals (PIs) for mean effect estimates, which summarize the likely range of true study effects,^45–47^ as well as shrinkage estimates and corresponding 95% PIs for individual studies. The latter provide an estimate of each study’s underlying true effect (eg, toxicity risk) by drawing on information from all available studies,^47^ and are useful for investigating heterogeneity. Meta-analyses were carried out using the bayesmeta^48^ package for R version 3.6.1 (R Foundation for Statistical Computing, Vienna, Austria).

## RESULTS

### LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process (full list of excluded studies available in Appendix C in Supplemental Materials).

Figure 2 Literature Flowchart

Notes. *47 studies in 52 publications.

Abbreviations. CINAHL=Cumulative Index for Nursing and Allied Health Literature; SR=systematic review.

### LITERATURE OVERVIEW

Our search identified 477 potentially relevant articles. Of these, 47 studies (in 52 publications)^1–32,36,49–66^ reported the results of treatment with PBT and met all inclusion criteria. No proton therapy manufacturers submitted information in response to our formal requests for scientific information. Fifteen studies (in 16 publications)^1–8,32,36,49,53,56,58,65,66^ reported data from a comparison population of patients who received IMRT or brachytherapy. All of the included studies were published after 2010 and generally reported data only on patients who were diagnosed with prostate cancer after 2000.

Using the ROBINS-I tool, 10 comparative studies (in 11 publications)^1–8,32,65,66^ were rated as low risk of bias, 3 were rated as moderate risk of bias, and 2 were rated as high risk of bias. Studies rated as low risk of bias were cohort studies using propensity score-based matching or weighting to limit selection bias risk. Characteristics of these studies are summarized in Table 1 (see Appendix D in Supplemental Materials for full study details). Seven studies compared PBT to IMRT as initial therapy for newly diagnosed prostate cancer patients,^1–6,66^ 2 compared PBT to brachytherapy for initial therapy of prostate cancer,^7,8^ and 1 study compared PBT to IMRT as postoperative adjuvant therapy following initial therapy with radical prostatectomy.^32,65^

Patients were followed for at least 12 months, and the most commonly reported outcomes were GI and GU toxicity. Six studies comparing PBT to IMRT as initial therapy for prostate cancer^1–5,66^ measured short- and/or intermediate-term GI symptoms (eg, rectal bleeding), GU symptoms (eg, urinary irritative or incontinence symptoms), or erectile dysfunction (ED). Symptoms were assessed with prospectively administered questionnaires (with results dichotomized into low and high severity) or by diagnosis and procedure codes contained in clinical administrative databases. One study^1^ also employed a prospectively measured general quality of life questionnaire. All studies reported intermediate-term outcomes, and 3 studies^1–3^ also reported acute GI and GU symptoms (defined as occurring within 90 days of treatment). An additional study^6^ examined risk of a new second cancer after primary treatment with PBT or IMRT.

Five comparative cohort studies^36,49,53,56,58^ were rated as moderate or high risk of bias mainly because they did not implement methods to sufficiently account for differences between treatment groups (see Appendix D in Supplemental Materials for full study details). These studies were not considered among the evidence addressing Key Questions 1 and 2 due to the risk of uncontrolled confounding. Thirty-two studies (in 36 publications)^9–31,50–52,54,55,57,59–64,67^ were case series in which all patients received PBT and provided evidence about whether benefits and harms of PBT vary by patient and/or treatment characteristics (Key Question 1a).

We identified 27 underway studies, 9 of which (5 RCTs) compare PBT to other treatment modalities (see Appendix F in Supplemental Materials for study details).

Table 1 Characteristics of Low Risk of Bias Studies Comparing PBT with IMRT or Brachytherapy

Author, Year; Sample Size | Study Design; Country | Mean/Median Age; Follow-up | Prostate Cancer Characteristics | PBT Dose (Gy); PBT Details | Comparator | Outcomes
Barsky 2021^32^ & Santos 2019^65^; N=307 | Retrospective cohort; US | NR; 5 years | Post-radical prostatectomy prostate cancer | 70.2 (median); NR | IMRT | Biochemical failure, overall survival, prostate cancer-specific survival
Coen 2012^8^; N=282 | Retrospective cohort; US | 66; 8 years | Localized prostate cancer | 79.2; Proton boost of 28.8 Gy before 3DCRT (79.2 Gy total) | Brachytherapy | Overall survival, biochemical failure, freedom from distant-metastasis
Dutz 2019^1^; N=58 | Prospective cohort; Germany | 72.7; 3 months–1 year | Localized prostate cancer | 74–76; 74–76 Gy in 37-38 fractions | IMRT | GU toxicity, GI toxicity, QoL
Fang 2014^2^; N=188 | Prospective cohort; US | NR; 3 months–2 years | Localized prostate cancer | 79.2; 79.2 Gy in 44 fractions | IMRT | GU toxicity, GI toxicity
Liu 2021^7^; N=276,880 | Retrospective cohort; US | 68; 10 years | Localized prostate cancer | ≥ 60; NR | Brachytherapy | Overall survival
Pan 2018^4^; N=3,434 | Retrospective cohort; US | <65; 2 years | Localized prostate cancer | 39 (median); NR | IMRT | GU toxicity, ED, QoL
Sheets 2012^66^; N=1,368 | Retrospective cohort; US | NR; 1 year | Localized prostate cancer | NR; NR | IMRT | GI toxicity, GU toxicity, ED
Vapiwala 2021^3^; N=1,850 | Prospective cohort; US | 67; 1 year | Localized early prostate cancer | 60–72.5; 2.5–3 Gy per fraction | IMRT | GU toxicity, GI toxicity
Xiang 2020^6^; N=10,700 | Retrospective cohort; US | 59.4; 5.21 years | Localized prostate cancer | 56.4-81.0; 2.5–5 Gy per fraction | IMRT | Second cancers
Yu 2013^5^; N=942 | Retrospective cohort; US | NR; 1 year | Localized early prostate cancer | NR; NR | IMRT | GU toxicity, GI toxicity

Notes. Barksy 2021^32^ is a follow-up analysis of Santos 2019.^65^

Abbreviations. 3DCRT=three-dimensional conformal radiation therapy; ED=erectile dysfunction; GI=gastrointestinal; GU=genitourinary; Gy=gray; IMRT=intensity modulated radiation therapy; PBT=proton beam therapy; QoL=quality of life.

### PROTON BEAM THERAPY COMPARED TO IMRT

#### Toxicity

Rates of moderate or severe toxicity symptoms varied across available studies. Early GI toxicity rates ranged from 4% to 17% among both IMRT and PBT patients, but the rates tended to be higher for IMRT patients in the 3 studies^1–3^ that reported on early toxicity. Rates of late GI toxicity (defined as symptoms that persist for 12 months or longer) ranged from 5% to 18%, and were lower among IMRT patients (4 studies^1–3,66^) or comparable for IMRT and PBT groups (2 studies^4,5^). Rates of early GU toxicity ranged from 0 to 45% and were consistently higher among patients receiving IMRT.^1–3^ Rates of late GU toxicity ranged from 2% to 32%, and were higher among IMRT patients (5 studies^1–4,66^) or comparable for both modalities (1 study^5^).

Studies that were sufficiently similar (see Methods section) were included in meta-analyses. A small number of such studies were available for each analysis after stratifying by trial endpoint. The majority of studies reported outcomes as counts or proportions in statistically matched cohorts, and risk ratios (RRs) were calculated directly for these studies. One study^3^ reported no toxicity events in 1 group, and a continuity correction of 0.5 was applied to all cell counts for this outcome. Adjusted odds ratios from 2 studies^2,5^ were converted to RRs using the square-root transformation.^68^ All synthesized ratios less than 1 indicate benefits (ie, reduced risk) for PBT compared to other radiation therapy modalities, and ratios greater than 1 indicate greater risk compared to other radiation therapy modalities. Results of meta-analyses are shown in Figure 3. Findings were not sensitive to prior information specified for heterogeneity in effects.

No pooled estimate of GI or GU toxicity risk reached statistical significance. At 3 months after treatment initiation or completion, results from 3 studies^1–3^ (N = 58–901) suggest a possible lower risk of early GI toxicity (RR_Mean_ = 0.76, 95% CI [0.39, 1.50]) and early GU toxicity (RR_Mean_ = 0.65, 95% CI [0.28, 1.34]) after treatment with PBT compared with IMRT. The largest study^3^ reported a significant finding for GU toxicity. Observed toxicity risk and estimates of true risk in each study (shown in blue in Figure 3) were consistent in direction (ie, at or below an RR of 1.0), and all studies used a similar outcome definition (CTCAE grade 2-3 or 2-3+).

Evidence on toxicity in the first year after treatment is more inconsistent. For GI toxicity, 2 small studies^1,2^ (N = 44–187) used the same outcome definition (CTCAE grade 2-3) and reported moderately to substantially greater risk of toxicity 1 year after treatment with PBT compared with IMRT. Risk estimates in these studies were highly imprecise, and in raw counts, differences between groups were minimal (1–6 toxicity events). Results of 2 larger studies^4,5^ (N = 942–3,434) were more precise and indicate no difference in risk (measured as ICD-9 bowel/GI toxicity regardless of severity). The pooled estimate also suggests little or no difference in GI toxicity risk between modalities (RR_Mean_ = 1.08, 95% CI [0.68, 1.95]). Estimates of true toxicity risk in each study suggest that the smaller studies may overestimate differences in GI toxicity risk.

Figure 3 Forest Plot of Toxicity Findings of Studies Comparing PBT to IMRT

Notes. Black diamonds indicate results of random-effects meta-analyses (width of diamond corresponds to 95% CI and gray dashed error bars to 95% PIs). Blue diamonds and error bars represent estimates of study-specific true effects (ie, shrinkage estimates) and corresponding 95% PIs (reflecting the likely range of true effects in each study). A continuity correction of 0.5 was applied to all 3-month GU toxicity cell counts reported by Vapiwala 2021.

Abbreviations. 95% CI=95% highest posterior density credible interval; CTCAE=Common Terminology Criteria for Adverse Events; Ctrl. %=outcome proportion in control group; HCPCS=Healthcare Common Procedure Coding System; ICD-9=International Classification of Diseases, 9^th^ Revision; Tx. %=outcome proportion in treatment group.

Evidence on GU toxicity 1 year after treatment is also inconsistent. Two studies^1,4^ that differ in size and outcome definition reported minimal difference in toxicity after treatment with PBT compared with IMRT. Two other studies^2,5^ (again inconsistent in size and outcome definition) observed somewhat lower toxicity risk after PBT. The larger of these studies^4^ reported a significant difference in risk, and the pooled result also indicates that GU toxicity risk is possibly lower after treatment with PBT compared with IMRT (RR_Mean_ = 0.82, 95% CI [0.57, 1.29]). Estimates of true GU toxicity risk in each study suggest that the difference in risk in all studies may more consistently favor PBT, while remaining fairly small in magnitude.

Two studies^2,4^ (N = 187–3,434) reported 24-month GI and GU toxicity outcomes (CTCAE grade 2-3 or ICD-9 bowel or composite urinary toxicity). Both studies reported higher GI toxicity risk after treatment with PBT compared with IMRT (RR_Mean_ = 1.29, 95% CI [0.68, 2.56]). For GU toxicity, studies reported no difference in risk^2^ or a somewhat (but significantly) lower risk^4^ after treatment with PBT compared with IMRT. Given the much larger size of the second study, pooling estimates from both studies also indicates possibly lower risk of GU toxicity after PBT compared with IMRT (RR_Mean_ = 0.81, 95% CI [0.44, 1.65]). Despite reporting similar GU toxicity risk for both modalities, the underlying risk of GU toxicity in the smaller study may favor PBT according to the estimate of true GU toxicity risk in that study.

Three studies (2 of which provided findings included in meta-analyses) reported on GI and GU toxicity over study observational periods that ranged from 24–80 months (median). All studies (N = 187–1,368) carried out statistical adjustment for confounding and excluded toxicity events that occurred in an early or acute period, defined as 3 months^2,3^ or 1 year.^66^ Studies were not pooled due to differences in outcome definitions, the duration of follow-up, and the excluded acute period. For GI toxicity, 2 studies used similarly defined outcomes (CTCAE grade 2-3 or 2+) and reported greater risk of GI toxicity after treatment with PBT compared with IMRT. Both results were nonsignificant and differed considerably in magnitude (hazard ratio = 1.24, 95% CI [0.53, 2.94];^2^ odds ratio = 2.68, 95% CI [0.80, 8.98]^3^). The third study^66^ assessed ICD-9 GI events of any severity and reported significantly greater GI toxicity risk after treatment with PBT compared with IMRT (RR = 1.52, 95% CI [1.27, 1.82]^i^). GU toxicity was reported by the same 3 studies, and estimates were consistent in direction (favoring PBT) and similar in magnitude (ratios ranged from 0.55 to 0.80), although none was significant.

One additional study^32,65^ (N = 260) examined rates of GI and GU toxicity in matched patients who received PBT or IMRT as “adjuvant” or “salvage” radiation after initial treatment with radical prostatectomy. Few details about the patients’ response to the initial prostatectomy were reported. Slightly higher rates of acute and late GI and GU toxicities were observed among IMRT recipients (differences were nonsignificant). Because this patient population differed substantially from those of other studies, this study was not included in meta-analyses.

Based on consistency in direction of reported findings across most comparative studies of GU toxicity—and across meta-analysis results and estimates of study-specific true GU toxicity risk—it is possible that PBT is associated with a somewhat lower risk of GU toxicity compared with IMRT. The magnitude of differences in risk varied across studies, however, and only 2 studies^3,4^ reported significantly lower risk among PBT recipients. Consistency in direction is less evident in findings on GI toxicity, although examining the pattern of available evidence suggests that GI toxicity attributable to PBT may be more likely outside of the early post-treatment period. Two studies reported significantly greater risk for PBT recipients in later periods.

Two retrospective cohort studies^4,66^ (N = 1,368–3,434) using clinical administrative data examined rates of ED after PBT and IMRT. Both studies accounted for potential confounders and used the same outcome (ICD-9 ED events) but differed in outcome timing. One study reported a significantly lower risk of ED among PBT recipients compared with those receiving IMRT at 2-year follow-up (hazard ratio = 0.71, 95% CI [0.59, 0.84]). In contrast, the second study observed a somewhat greater risk of ED for PBT recipients at a median of 46–50 months post-treatment (RR = 1.12, 95% CI [0.89, 1.43]).

As noted initially, no meta-analytic findings reached significance. Moreover, despite the consistency in direction of GU findings (and some suggestive trends in GI findings), studies used inconsistent outcome definitions (some restricting to more severe outcomes, others counting toxicity at any severity), varied considerably in size, and may also have differed in PBT dosing. The impact of dosing differences is unclear because not all studies reported dosages. With these considerations in mind, we concluded that available evidence on the comparative risk of GI and GU toxicity following PBT and IMRT is low strength. Evidence is insufficient for reaching a conclusion about differences in risk of post-treatment ED after PBT or IMRT.

#### Quality of Life and Survival

One small study^1^ (29 matched pairs of patients receiving either PBT or IMRT) prospectively administered a general quality of life measure 3 months and 12 months after PBT or IMRT. No subscale scores were significantly different between modalities. Long-term cancer control has been evaluated using patient survival or by elevated post-treatment levels of prostate-specific antigen (PSA; a marker of disease progression). One study^7^ examined overall survival among patients enrolled in the National Cancer Database from 2004–2015 who received initial therapy with PBT or external beam photon therapy (either IMRT or 3-dimensional conformal radiation therapy). Ten-year survival rates in 1,860 matched patient pairs were significantly higher in the PBT group (80.1% vs 71.3%). Because study outcomes were not disaggregated by external beam modality, it is unclear to what extent these results correspond to a direct comparison between PBT and IMRT. The study also does not provide information on any changes to PBT techniques over the 10-year study period. Evidence is insufficient to draw conclusions about differences in quality of life or survival after PBT or IMRT.

#### Incidence of Second Cancers

One study^6^ assessed incidence of second cancers among patients who received PBT or IMRT. The study used a retrospective cohort design, and the data were derived from a nationwide cancer registry in the US. A limitation of this data source is that a second cancer was coded only as having occurred, with no information about its timing, location, or histology. The investigators employed propensity scores to match the PBT and IMRT patients with regards to various clinical and sociodemographic characteristics, and statistical models were also adjusted for covariates. A total of 3,566 prostate cancer patients who received PBT as their primary treatment for cancer were matched 2 to 1 to 7,134 patients who received IMRT. We judged this study to have a low risk of bias. The adjusted odds ratio for second cancer was 0.18, 95% CI [0.14, 0.24]. Despite the low risk of bias in this study, there are inherent limitations in the data used in this study. The time-course of second cancer occurrence was not reported, as well as any data that would provide information about whether second cancers occurred in anatomical locations that plausibly received radiation exposure. Available evidence^ii^ is therefore insufficient to reach a conclusion about comparative risk of second cancers after PBT or IMRT.

### PROTON BEAM THERAPY COMPARED TO BRACHYTHERAPY

For the direct comparison of PBT to brachytherapy, only 2 comparative studies^7,8^ employed adequate methods to control for confounding. Both studies examined markers of long-term disease control. The first^7^ assessed overall survival for patients receiving initial therapy with PBT or brachytherapy who were enrolled in the National Cancer Database between 2004 and 2015. In 1,860 matched pairs, 10-year survival rates were similar between the PBT and brachytherapy groups (80.1% and 78.3%, respectively). The second study^8^ examined overall survival and cancer progression as measured by PSA levels in 141 matched pairs of men receiving either PBT or brachytherapy. There were no significant differences between the 2 cohorts in either outcome. A limitation of this study was that an older form of combined proton and photon therapy (“proton boost”) was used. Evidence that PBT and brachytherapy confer similar impacts on overall survival was rated as low strength.

### NONCOMPARATIVE STUDIES OF PROTON BEAM THERAPY

The remaining evidence on the effectiveness of PBT consists of studies based on case series. Thirty-two studies (in 36 publications)^9–31,50–52,54,55,57,59–64,67,70^ attempted to compare subgroups of patients who received PBT, and these studies were assessed for whether they provide insight into differences in clinical outcomes between subgroups defined by patient characteristics or by differences in the technical aspects of how the PBT was delivered (Key Question 1a).

Ten studies^9–13,15,16,26,60^ (N = 192–2,021) assessed the relationship between patient characteristics and the incidence of late GU or GI toxicity. Factors associated with a higher incidence of GU toxicity were older age^12,15,26^ and a history of prior prostate surgery.^16,60^ Another case series^54^ that used multivariate analysis did not find that age was a predictor of urinary toxicity. For GI toxicity, age was only a weak predictor,^15,26^ but use of anticoagulants was associated with a higher rate of rectal bleeding after PBT (low strength of evidence).^11–13^

Three studies^14,55,71^ (N = 127–1,005) have examined the relationship between patient characteristics and sexual function following PBT. Pre-existing cardiac disease^55^ and older age^71^ were associated with ED following PBT. In a study of the relationship between baseline cancer risk scores and sexual function following PBT, low-risk patients had better sexual function prior to treatment but greater decline following treatment.^14^ All studies were exploratory and examined different patient characteristics; therefore evidence is insufficient to make conclusions about the effect of patient factors on sexual function.

Single studies have examined other patient factors, including prostate size^52^ (N = 81), the duration of androgen deprivation therapy^63^ (N = 1,075), and the time of day that PBT sessions occurred^64^ (N = 168). These studies did not report data on control groups, and none made a conclusive contribution to the evidence base.

In a study^10^ of the effect of patient race on GU and GI toxicity rates after PBT, 92 black patients were matched to 92 white patients. No difference in toxicity rates was found between the 2 groups. These results were similar to another study^9^ (N = 1,066) that compared racial groups but did not use a matching methodology. Overall, the strength of evidence for race not affecting outcomes is low due to the small number of studies and lack of data on all races/ethnicities.

Thirteen studies have examined the relationship between patient factors and rates of cancer control^9,10,12,15–24,26,71^ (N = 93–1,327). The most commonly used methods for defining subgroups were measures of risk of cancer recurrence based on baseline data such as patient age, tumor stage, Gleason score, and PSA level. Most studies found that men who had worse baseline risk scores had modestly higher rates of disease progression as measured by PSA levels, though most also found that the rates of 5-year disease progression were generally less than 25% in all risk groups who received PBT as initial therapy for prostate cancer. Two studies^12,23^ found very low rates of disease progression and no relationship with risk score. Because of the generally small influence of risk score on disease progression, evidence that baseline risk score predicts the rate of disease progression after PBT is low strength.

### EFFECT OF DOSAGE SCHEDULES AND OTHER TECHNOLOGICAL FACTORS ON PATIENT OUTCOMES

Several clinical studies have examined whether dosage schedule (use of hypofractionation), use of pencil beam modality, and total delivered dose influence outcomes. Hypofractionation has been examined in 2 small RCTs.^27,30^ The first RCT^27^ randomized 82 men to a “moderate hypofractionated” PBT dose schedule or an “extreme hypofractionated” schedule and compared long-term GI and GU toxicity and cancer control. The rates of GI and GU toxicity were slightly different between treatment arms, but these differences were not statistically significant. Cancer progression as measured by PSA levels was significantly higher in the extreme hypofractionation arm. The second RCT^30^ (N = 82) reported small and nonsignificant differences in GU and GI toxicity between patients on a hypofractionation schedule or conventional dosage schedule.

Two observational studies^28,29^ (N = 289–526) compared patients receiving hypofractionation to patients receiving conventional dosage schedules. Though there were few baseline differences in demographic characteristics between groups, neither study used statistical methods to control for confounding. Both found only small differences in GU and GI toxicity rates between groups. Despite similar conclusions across all 4 studies on hypofractionation, RCTs were small and employed different comparators, and other studies had critical methodological limitations. For these reasons, the strength of evidence on hypofractionated dosing schedules is low. One of the included RCTs^27^ also examined long-term cancer control with hypofractionation, but all patients received some degree of hypofractionation, hindering any conclusion about cancer control.

Pencil beam scanning (PBS) is a newer technique that potentially can deliver more precise dosing in PBT, compared with conventional PBT. A multi-site registry study (N = 1,343) has enrolled patients receiving either PBS or conventional PBT and has reported data on toxicity rates for the 2 alternative modalities.^61,62^ Both acute and late GU toxicity were higher in the PBS group, while GI and sexual toxicity did not differ between the groups. The methods for controlling for confounding were limited in this study. Overall, the current evidence is insufficient to draw conclusions about the comparison of PBS to conventional PBT.

Few studies examined the relationship between total radiation dose and outcomes among patients who received PBT. One study^67^ (N = 218) measured toxicity rates among patients receiving a total dose of either 70 GyE, 74 GyE, or 78 GyE. Significantly higher rates of late GI toxicity were observed in the 78 GyE group compared with the lower dosages. Rates of severe late GU toxicity and sexual function scores did not significantly differ between dosage groups. Another case series found an association between total dose and GI toxicity using a multivariable model.^50^ Overall, available evidence is insufficient to draw conclusions about the influence of total radiation dose on toxicity risk.

### PROTON BEAM THERAPY FOR PATIENTS WITH RECURRENT PROSTATE CANCER

One study^32,65^ (N = 307) that used case matching reported on cancer control in patients who received either PBT or IMRT following relapse of prostate cancer and initial therapy with radical prostatectomy. The study reported data from patients who had received “adjuvant” PBT or IMRT, and it is not possible to distinguish between the relapse and adjuvant subgroups. The rates of further disease progression as measured by PSA rise were moderately high (30-45%, depending on the definition used for interpreting PSA rise) and similar between the PBT and IMRT groups. Five-year cancer-specific mortality was low in both PBT and IMRT groups. Two other studies^57,72^ (N = 100–102) reported cancer control data for patients who received PBT following relapse after initial therapy with radical prostatectomy. These studies did not have comparison groups of patients who received another form of therapy for the relapse. The 5-year rate of disease progression (by PSA rise) was 42% and 39% in these studies, which is similar to the rate reported for the PBT arm of the comparative study. Due to the small number of studies, evidence is insufficient to conclude whether PBT has advantages over other forms of therapy for the treatment of relapsed prostate cancer.

### PREVIOUSLY PUBLISHED SYSTEMATIC REVIEWS

The present review updates an evidence synthesis completed in 2015,^37^ focusing on use of PBT for prostate cancer. The 2015 review included several studies that were not included in the present review because they compared PBT to older modes of conventional radiation therapy. IMRT is currently the dominant modality used for photon-based radiation therapy in the US, and for the present review, eligible comparison conditions were limited to IMRT and brachytherapy to reflect active treatment options now available to newly diagnosed prostate cancer patients in the US. Risks of bias in these studies was assessed using the ROBINS-I methodology.

The 2015 evidence synthesis reported generally similar outcomes between PBT and photon-based radiation therapy and concluded that there was not enough evidence on the effectiveness of PBT to determine whether it was better, worse, or equivalent to conventional therapies for prostate cancer (low strength of evidence ratings for all conclusions). The present review includes studies published since 2015 that compare GU and GI toxicity risk among patients receiving PBT or IMRT, yet the strength of evidence for these outcomes remains low. In 2021, Ontario Health released a review of other systematic reviews on PBT,^73^ with findings similar to those of the present review and low strength of evidence ratings for all conclusions. Another 2021 systematic review^74^ focused on the comparison between PBT and carbon ion radiotherapy, but did not perform meta-analyses on studies comparing PBT to photon-based radiation therapy nor report strength of evidence ratings.

## DISCUSSION

Over the last 2 decades, PBT has evolved into a mature technology for treatment of men with recently diagnosed prostate cancer. In this period, the number of PBT treatment centers has greatly increased in the United States. Nonetheless, other types of radiation therapy (particularly IMRT) are used much more frequently than PBT. The evidence base on radiation therapy for the treatment of prostate cancer includes few controlled trials of alternative treatment modalities. Instead, the best available evidence comes from small to medium-sized cohort studies that compare PBT to IMRT. Fewer studies compare PBT to brachytherapy, but those that are available provide some insights.

For men who choose to pursue radiation therapy as initial treatment for prostate cancer, the choice among PBT, IMRT, and brachytherapy can be informed by data about the relative benefits and harms of these modalities. The primary potential benefit of any of these treatments is to provide protection against relapse and progression of the cancer. The available evidence is insufficient to draw a conclusion about the comparative benefits of PBT and IMRT for cancer control. Although uncontrolled studies^9,10,12,15–24,26,71^ suggest that relapse rates for PBT are low, there are few data directly comparing PBT to IMRT. The evidence is stronger (though overall low strength) that PBT and brachytherapy confer similar levels of cancer control.

Studies in men who received either radiation therapy, surgical prostatectomy, or active surveillance for prostate cancer have found that radiation therapy is associated with higher rates of undesirable urinary symptoms or bowel problems.^75,76^ While a theoretical advantage of PBT is that protons deliver radiation to tissues in a highly targeted fashion, the available evidence has not conclusively shown superiority of PBT for GU and GI toxicities and sexual problems. PBT may be superior to IMRT for one category of treatment toxicity (GU side effects), but the strength of evidence is low and differences in risk between modalities may be modest. Other toxicities (GI and sexual) do not appear to differ substantially between PBT and IMRT, though the strength of evidence for this conclusion is also low. There is insufficient evidence to draw conclusions about differences in toxicity between PBT and brachytherapy.

Hypofractionation can potentially reduce patient burden by requiring fewer sessions to complete a course of radiation therapy. Low-strength evidence from a small number of studies indicates similar GI and GU toxicity rates for hypofractionation and conventional dosing in PBT. Evidence about whether certain patient characteristics lead to differences in clinical outcomes comes mostly from uncontrolled single-arm studies of patients receiving PBT. These results might assist clinicians in increasing patients’ understanding of their risk of toxicity when undergoing PBT. However, because of a lack of comparative data for similar patients receiving other forms of radiation therapy, existing studies do not clarify whether specific patient subgroups experience greater treatment benefits or harm—and consequently may be better candidates for PBT than for alternative modalities.

### LIMITATIONS

Evidence comparing PBT to IMRT or brachytherapy for initial treatment of prostate cancer is derived from observational studies of patient cohorts receiving either PBT or the alternative modality. Although 10 of these comparative studies were judged to have low risk of bias, various unmeasured confounders (such as the effect of differing patient referral patterns in multiple participating institutions) could affect the study results. This limitation, among others discussed elsewhere, reduces the strength of available evidence. There are also potential limitations of our review methodology, including use of a second reviewer to check for study selection and data abstraction rather than fully independent dual review.

### FUTURE RESEARCH

Prospective randomized trials can avoid biases inherent to studies with observational designs. Several RCTs are underway that will compare clinical outcomes of patients receiving PBT or photon-based radiation therapy, and when reported later this decade, trial findings may resolve open questions about PBT for the treatment of localized prostate cancer.

### CONCLUSIONS

The evidence base on comparative benefits and harms of PBT for the initial treatment of prostate cancer continues to grow. Nonetheless, available evidence remains low or insufficient strength. Based on studies published through the end of 2021, it is possible that PBT is associated with lower risk of early and late GU toxicity compared with IMRT. Rates of early and late GI toxicity and sexual side effects appear to be similar between PBT and IMRT. Available evidence is insufficient to determine whether risk of GU and GI toxicity differs between PBT and brachytherapy. Based on a single comparative study using full-dose PBT, relapse rates appear to be similar for PBT and brachytherapy, while evidence on relapse prevention for PBT compared with IMRT is insufficient.

More studies are needed to address evidence gaps, including cancer recurrence rates following PBT and IMRT, toxicity among comparable patients receiving PBT or brachytherapy, and use of PBT in cases of prostate cancer relapse after initial treatment with another therapy. Several controlled clinical trials are currently underway and could address some open questions. Currently available evidence may be useful in patient-provider decisions about the treatment of localized prostate cancer, yet it also reveals important uncertainties that are necessary to consider in the complex and nuanced choice of treatment modality.

i Risk ratios reported by this study compared IMRT to PBT (ie, values larger than 1 indicate greater risk for IMRT). Results from this study were inverted for consistency with other risk estimates.

ii Another identified study^69^ examined rates of second malignancies for patients who received either PBT or photon-based radiation therapy, but this study was excluded because nearly all PBT patients were treated prior to 2000 at a single proton therapy center, and few photon-treated patients appeared to have received modern external beam modalities such as IMRT.

## REFERENCES

1 Dutz A, Agolli L, Baumann M, . Early and late side effects, dosimetric parameters and quality of life after proton beam therapy and IMRT for prostate cancer: a matched-pair analysis. Acta Oncologica. 2019;58(6):916–925.30882264
2 Fang P, Mick R, Deville C, . A case-matched study of toxicity outcomes after proton therapy and intensity-modulated radiation therapy for prostate cancer. Cancer. 2014;121(7):1118–1127.25423899
3 Vapiwala N, Wong JK, Handorf E, . A Pooled Toxicity Analysis of Moderately Hypofractionated Proton Beam Therapy and Intensity Modulated Radiation Therapy in Early-Stage Prostate Cancer Patients. International Journal of Radiation Oncology, Biology, Physics. 2021;110(4):1082–1089.33539968
4 Pan HY, Jiang J, Hoffman KE, . Comparative Toxicities and Cost of Intensity-Modulated Radiotherapy, Proton Radiation, and Stereotactic Body Radiotherapy Among Younger Men With Prostate Cancer. Journal of Clinical Oncology. 2018;36(18):1823–1830.29561693
5 Yu JB, Soulos PR, Herrin J, . Proton Versus Intensity-Modulated Radiotherapy for Prostate Cancer: Patterns of Care and EarlyToxicity. JNCI : Journal of the National Cancer Institute. 2013;105(1):25–32.23243199
6 Xiang M, Chang DT, Pollom EL. Second cancer risk after primary cancer treatment with three-dimensional conformal, intensity-modulated, or proton beam radiation therapy. Cancer. 2020;126(15):3560–3568.32426866
7 Liu Y, Patel SA, Jani AB, . Overall Survival After Treatment of Localized Prostate Cancer With Proton Beam Therapy, External-Beam Photon Therapy, or Brachytherapy. Clinical Genitourinary Cancer. 2021;19(3):255–266.e257.32972877
8 Coen JJMD, Zietman ALMD, Rossi CJMD, . Comparison of High-Dose Proton Radiotherapy and Brachytherapy in Localized Prostate Cancer: A Case-Matched Analysis. International journal of radiation oncology, biology, physics. 2012b;82(1):e25–e31.21470787
9 Bryant C, Hoppe BS, Henderson RH, . Race Does Not Affect Tumor Control, Adverse Effects, or Quality of Life after Proton Therapy. International Journal of Particle Therapy. 2017;3(4):461–472.31772996
10 Bryant C, Mendenhall NP, Henderson RH, . Does Race Influence Health-related Quality of Life and Toxicity Following Proton Therapy for Prostate Cancer? American Journal of Clinical Oncology. 2016;39(3):261–265.24710124
11 Colaco RJ, Hoppe BS, Flampouri S, . Rectal toxicity after proton therapy for prostate cancer: an analysis of outcomes of prospective studies conducted at the university of Florida Proton Therapy Institute. International Journal of Radiation Oncology, Biology, Physics. 2015;91(1):172–181.25442338
12 Grewal AS, Schonewolf C, Min EJ, . Four-Year Outcomes From a Prospective Phase II Clinical Trial of Moderately Hypofractionated Proton Therapy for Localized Prostate Cancer. International Journal of Radiation Oncology, Biology, Physics. 2019;105(4):713–722.31199994
13 Lee HJ, Jr., Macomber MW, Spraker MB, . Analysis of Gastrointestinal Toxicity in Patients Receiving Proton Beam Therapy for Prostate Cancer: A Single-Institution Experience. Advances in radiation oncology. 2019;4(1):70–78.30706013
14 Hattori Y, Iwata H, Nakajima K, . Changes in sexual function and serum testosterone levels in patients with prostate cancer after image-guided proton therapy. Journal of Radiation Research. 2021;62(3):517–524.33675355
15 Takagi M, Demizu Y, Fujii O, . Proton Therapy for Localized Prostate Cancer: Long-Term Results From a Single-Center Experience. International Journal of Radiation Oncology, Biology, Physics. 2020;109(4):964–974.33186616
16 Bryant C, Smith TL, Henderson RH, . Five-Year Biochemical Results, Toxicity, and Patient-Reported Quality of Life After Delivery of Dose-Escalated Image Guided Proton Therapy for Prostate Cancer. International Journal of Radiation Oncology, Biology, Physics. 2016;95(1):422–434.27084658
17 Henderson RH, Bryant C, Hoppe BS, . Five-year outcomes from a prospective trial of image-guided accelerated hypofractionated proton therapy for prostate cancer. Acta Oncologica. 2017;56(7):963–970.28514929
18 Henderson RH, Bryant CM, Nichols RC, . Five- and seven-year outcomes for image-guided moderately accelerated hypofractionated proton therapy for prostate cancer. Acta Oncologica. 2021:1–10.33412980
19 Iwata H, Ishikawa H, Takagi M, . Long-term outcomes of proton therapy for prostate cancer in Japan: a multi-institutional survey of the Japanese Radiation Oncology Study Group. Cancer Medicine. 2018;7(3):677–689.29441697
20 Johansson S, Isacsson U, Sandin F, Turesson I. High efficacy of hypofractionated proton therapy with 4 fractions of 5Gy as a boost to 50Gy photon therapy for localized prostate cancer. Radiotherapy & Oncology. 2019;141:164–173.31431382
21 Kubes J, Haas A, Vondracek V, . Ultrahypofractionated Proton Radiation Therapy in the Treatment of Low and Intermediate-Risk Prostate Cancer-5-Year Outcomes. International Journal of Radiation Oncology, Biology, Physics. 2021;110(4):1090–1097.33587990
22 Kubes J, Vondracek V, Andrlik M, . Extreme hypofractionated proton radiotherapy for prostate cancer using pencil beam scanning: Dosimetry, acute toxicity and preliminary results. Journal of Medical Imaging & Radiation Oncology. 2019;63(6):829–835.31486267
23 Makishima H, Ishikawa H, Tanaka K, . A retrospective study of late adverse events in proton beam therapy for prostate cancer. Molecular & Clinical Oncology. 2017;7(4):547–552.29046789
24 Mendenhall N, Hoppe B, Nichols R, . Five-year outcomes from 3 prospective trials of image-guided proton therapy for prostate cancer. Int J Radiat Oncol Biol Phys. 2014;88(3):596–602.24521677
25 Ho CK, Bryant CM, Mendenhall NP, . Long-term outcomes following proton therapy for prostate cancer in young men with a focus on sexual health. Acta Oncologica. 2018;57(5):582–588.29359988
26 Takagi M, Demizu Y, Terashima K, . Long-term outcomes in patients treated with proton therapy for localized prostate cancer. Cancer Medicine. 2017;6(10):2234–2243.28879658
27 Ha B, Cho KH, Lee KH, . Long-term results of a phase II study of hypofractionated proton therapy for prostate cancer: moderate versus extreme hypofractionation. Radiation Oncology. 2019;14(1):4.30630500
28 Iizumi T, Ishikawa H, Sekino Y, . Acute toxicity and patient-reported symptom score after conventional versus moderately hypofractionated proton therapy for prostate cancer. Journal of Medical Radiation Sciences. 2021;19:19.
29 Nakajima K, Iwata H, Ogino H, . Acute toxicity of image-guided hypofractionated proton therapy for localized prostate cancer. International Journal of Clinical Oncology. 2018;23(2):353–360.29098520
30 Vargas CE, Hartsell WF, Dunn M, . Hypofractionated Versus Standard Fractionated Proton-beam Therapy for Low-risk Prostate Cancer: Interim Results of a Randomized Trial PCG GU 002. American Journal of Clinical Oncology. 2018;41(2):115–120.26523442
31 Vargas CE, Schmidt MQ, Niska JR, . Initial toxicity, quality-of-life outcomes, and dosimetric impact in a randomized phase 3 trial of hypofractionated versus standard fractionated proton therapy for low-risk prostate cancer. Advances in radiation oncology. 2018;3(3):322–330.30202801
32 Barsky AR, Carmona R, Verma V, . Comparative Analysis of 5-Year Clinical Outcomes and Patterns of Failure of Proton Beam Therapy Versus Intensity Modulated Radiation therapy for Prostate Cancer in the Postoperative Setting. Practical Radiation Oncology. 2021;11(2):e195–e202.33242634
33 Siegel RL, Miller KD, Fuchs HE, Jemal A. Cancer Statistics, 2021. CA Cancer J Clin. 2021;71(1):7–33.33433946
34 Feletto E, Bang A, Cole-Clark D, Chalasani V, Rasiah K, Smith DP. An examination of prostate cancer trends in Australia, England, Canada and USA: Is the Australian death rate too high? In. World J Urol. Vol 33. 2015/02/24 ed2015:1677–1687.25698456
35 Halpern JA, Sedrakyan A, Hsu WC, . Use, complications, and costs of stereotactic body radiotherapy for localized prostate cancer. In. Cancer (0008543X). Vol 122. Hoboken, New Jersey: John Wiley & Sons, Inc.; 2016:2496–2504.
36 Halpern JA, Sedrakyan A, Hsu WC, . Use, complications, and costs of stereotactic body radiotherapy for localized prostate cancer. Cancer. 2016;122(16):2496–2504.27224858
37 Peterson K, McCleery E, Waldrip K, Helfand M. Comparative Effectiveness of Proton Irradiation Treatment. In. VA ESP Project #09-199;2015.
38 Thomson H, Craig P, Hilton-Boon M, Campbell M, Katikireddi SV. Applying the ROBINS-I tool to natural experiments: an example from public health. Systematic Reviews. 2018;7(1):15.29368630
39 Berkman ND, Lohr KN, Ansari MT, . Grading the strength of a body of evidence when assessing health care interventions: an EPC update. J Clin Epidemiol. 2015;68(11):1312–1324.25721570
40 Higgins JP, Thompson SG, Spiegelhalter DJ. A re-evaluation of random-effects meta-analysis. J R Stat Soc Ser A Stat Soc. 2009;172(1):137–159.
41 Röver C. Bayesian Random-Effects Meta-Analysis Using the bayesmeta R Package. Journal of Statistical Software. 2020;93(6).
42 Friede T, Röver C, Wandel S, Neuenschwander B. Meta-analysis of two studies in the presence of heterogeneity with applications in rare diseases. Biometrical Journal. 2017;59(4):658–671.27754556
43 Friede T, Röver C, Wandel S, Neuenschwander B. Meta-analysis of few small studies in orphan diseases. Research Synthesis Methods. 2017;8(1):79–91.27362487
44 Röver C, Bender R, Dias S, . On weakly informative prior distributions for the heterogeneity parameter in Bayesian random-effects meta-analysis. Res Synth Methods. 2021;12(4):448–474.33486828
45 Borenstein M, Higgins JP, Hedges LV, Rothstein HR. Basics of meta-analysis: I2 is not an absolute measure of heterogeneity. Res Synth Methods. 2017;8(1):5–18.28058794
46 Parr NJ, Schweer-Collins ML, Darlington TM, Tanner-Smith EE. Meta-analytic approaches for examining complexity and heterogeneity in studies of adolescent development. J Adolesc. 2019;77:168–178.31739275
47 van Aert RCM, Schmid CH, Svensson D, Jackson D. Study specific prediction intervals for random-effects meta-analysis: A tutorial: Prediction intervals in meta-analysis. Res Synth Methods. 2021;12(4):429–447.33939307
48 Röver C, Friede T. bayesmeta: Bayesian Random-Effects Meta-Analysis and Meta-Regression. The Comprehensive R Archive Network. https://cran.r-project.org/web/packages/bayesmeta/index.html. Published 2022. Accessed June, 2022.
49 Bai M, Gergelis KR, Sir M, . Comparing bowel and urinary domains of patient-reported quality of life at the end of and 3 months post radiotherapy between intensity-modulated radiotherapy and proton beam therapy for clinically localized prostate cancer. Cancer Medicine. 2020;9(21):7925–7934.32931662
50 Bulman GF, Bhangoo RS, DeWees TA, . Dose-volume histogram parameters and patient-reported EPIC-Bowel domain in prostate cancer proton therapy. Radiation Oncology Journal. 2021;39(2):122–128.34619829
51 Deville C, Hwang W-T, Barsky AR, . Initial clinical outcomes for prostate cancer patients undergoing adjuvant or salvage proton therapy after radical prostatectomy. In. Vol 59. Philadelphia, Pennsylvania: Taylor & Francis Ltd; 2020:1235–1239.
52 Goenka A, Newman NB, Fontanilla H, . Patient-reported Quality of Life After Proton Beam Therapy for Prostate Cancer: The Effect of Prostate Size. Clinical Genitourinary Cancer. 2017;15(6):704–710.28412047
53 Gray PJ, Paly JJ, Yeap BY, . Patient-reported outcomes after 3-dimensional conformal, intensity-modulated, or proton beam radiotherapy for localized prostate cancer. Cancer. 2013;119(9):1729–1735.23436283
54 Henderson RH, Hoppe BS, Marcus RB, . Urinary functional outcomes and toxicity five years after proton therapy for low- and intermediate-risk prostate cancer: Results of two prospective trials. Acta Oncologica. 2013;52(3):463–469.23477359
55 Holtzman AL, Bryant CM, Mendenhall NP, . Patient-Reported Sexual Survivorship Following High-Dose Image-Guided Proton Therapy for Prostate Cancer. Radiotherapy & Oncology. 2019;134:204–210.31005217
56 Hoppe BS, Michalski JM, Mendenhall NP, . Comparative effectiveness study of patient-reported outcomes after proton therapy or intensity-modulated radiotherapy for prostate cancer. Cancer. 2014;120(7):1076–1082.24382757
57 Kharod SM, Mercado CE, Morris CG, . Postoperative or Salvage Proton Radiotherapy for Prostate Cancer After Radical Prostatectomy. International Journal of Particle Therapy. 2021;7(4):52–64.33829073
58 Kim S, Shen S, Moore DF, . Late Gastrointestinal Toxicities Following Radiation Therapy for Prostate Cancer. European urology. 2011;60(5):908–916.21684064
59 Kim Y-J, Cho KH, Pyo HR, . A phase II study of hypofractionated proton therapy for prostate cancer. Acta Oncologica. 2013;52(3):477–485.23398594
60 Lee DT, Mendenhall NP, Smith TL, . Patient-Reported Quality of Life in Men with Transurethral Resection of the Prostate Undergoing Proton Therapy for Management of Prostate Cancer. International Journal of Particle Therapy. 2016;2(4):518–524.30079368
61 Mishra MV, Khairnar R, Bentzen SM, . Patient reported outcomes following proton pencil beam scanning vs. passive scatter/uniform scanning for localized prostate cancer: Secondary analysis of PCG 001-09. Clinical and Translational Radiation Oncology. 2020;22:50–54.32258443
62 Mishra MV, Khairnar R, Bentzen SM, . Proton beam therapy delivered using pencil beam scanning vs. passive scattering/uniform scanning for localized prostate cancer: Comparative toxicity analysis of PCG 001-09. Clinical and Translational Radiation Oncology. 2019;19:80–86.31650043
63 Murakami M, Ishikawa H, Shimizu S, . Optimal Androgen Deprivation Therapy Combined with Proton Beam Therapy for Prostate Cancer: Results from a Multi-Institutional Study of the Japanese Radiation Oncology Study Group. Cancers. 2020;12(6):25.
64 Negoro H, Iizumi T, Mori Y, . Chronoradiation Therapy for Prostate Cancer: Morning Proton Beam Therapy Ameliorates Worsening Lower Urinary Tract Symptoms. Journal of Clinical Medicine. 2020;9(7):16.
65 Santos PMG, Barsky AR, Hwang WT, . Comparative toxicity outcomes of proton-beam therapy versus intensity-modulated radiotherapy for prostate cancer in the postoperative setting. Cancer. 2019;125(23):4278–4293.31503338
66 Sheets NC, Goldin GH, Meyer A-M, . Intensity-Modulated Radiation Therapy, Proton Therapy, or Conformal Radiation Therapy and Morbidity and Disease Control in Localized Prostate Cancer. JAMA : the Journal of the American Medical Association. 2012;307(15):1611–1620.22511689
67 Arimura T, Yoshiura T, Matsukawa K, Kondo N, Kitano I, Ogino T. Proton Beam Therapy Alone for Intermediate- or High-Risk Prostate Cancer: An Institutional Prospective Cohort Study. Cancers. 2018;10(4):10.
68 VanderWeele TJ. Optimal approximate conversions of odds ratios and hazard ratios to risk ratios. In. Biometrics. Vol 76. 2019/12/07 ed2020:746–752.
69 Chung C, Yock T, Nelson K, Xu Y, Keating N, Tarbell N. Incidence of Second Malignancies Among Patients Treated with Proton versus Photon Radiation. International Journal of Radiation Oncology, Biology, Physics. 2013;87(1).
70 Lee HJ, Macomber MW, Spraker MB, . Early toxicity and patient reported quality-of-life in patients receiving proton therapy for localized prostate cancer: a single institutional review of prospectively recorded outcomes. In. Radiation Oncology. Vol 13: BioMed Central; 2018:N.PAG-N.PAG.
71 Ho CK, Bryant CM, Mendenhall NP, . Long-term outcomes following proton therapy for prostate cancer in young men with a focus on sexual health. In. Acta Oncologica. Vol 57 2018:582–588.29359988
72 Deville C, Jr., Hwang WT, Barsky AR, . Initial clinical outcomes for prostate cancer patients undergoing adjuvant or salvage proton therapy after radical prostatectomy. In. Acta Oncologica. Vol 59 2020:1235–1239.32421456
73 Ontario H. Proton Beam Therapy for Cancer in Children and Adults: A Health Technology Assessment. In. Ontario Health Technology Assessment Series. Vol 21 2021:1–142.
74 Li M, Li X, Yao L, . Clinical Efficacy and Safety of Proton and Carbon Ion Radiotherapy for Prostate Cancer: A Systematic Review and Meta-Analysis. In. Frontiers in Oncology. Vol 11 2021:709530.34712607
75 Barocas DA, Alvarez J, Resnick MJ, . Association Between Radiation Therapy, Surgery, or Observation for Localized Prostate Cancer and Patient-Reported Outcomes After 3 Years. JAMA. 2017;317(11):1126–1140.28324093
76 Chen RC, Basak R, Meyer A-M, . Association Between Choice of Radical Prostatectomy, External Beam Radiotherapy, Brachytherapy, or Active Surveillance and Patient-Reported Quality of Life Among Men With Localized Prostate Cancer. JAMA. 2017;317(11):1141–1150.28324092

## Supplemental Materials

Download Supplemental Materials PDF

### APPENDIX A SEARCH STRATEGY

#### SYSTEMATIC REVIEWS

Search for current systematic reviews (limited to last 7 years); Date Searched: 02-07-22
A. Bibliographic Databases: | # | Search Statement | Results
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to February 04, 2022 | [underlined: 1] | exp Prostatic Neoplasms/ OR (prostate neoplasm$1 OR prostate cancer$1 OR prostatic cancer$1 OR prostatic neoplasm$1).ti,ab. | 173582
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to February 04, 2022 | [underlined: 2] | Protons/ OR Proton Therapy/ OR (proton* OR (proton adj2 therap*)).ti,ab. | 159620
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to February 04, 2022 | [underlined: 3] | 1 AND 2 | 1074
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to February 04, 2022 | [underlined: 4] | [underlined: (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt.] | [underlined: 499549]
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to February 04, 2022 | [underlined: 5] | 3 and 4 | 37
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to February 04, 2022 | [underlined: 6] | limit 5 to english language and yr=“2015-current” | 21
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to December 02, 2021 | [underlined: 1] | Prostatic Neoplasms.kw. OR (prostate neoplasm$1 OR prostate cancer$1 OR prostatic cancer$1 OR prostatic neoplasm$1).ti,ab. | 52
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to December 02, 2021 | [underlined: 2] | (Protons OR Proton Therapy).kw. OR (proton* OR (proton adj2 therap*)).ti,ab. | 29
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to December 02, 2021 | [underlined: 3] | 1 AND 2 | 0

Search for current systematic reviews (limited to last 7 years); Date Searched: 02-07-22
B. Non-bibliographic databases | [underlined: Evidence] | [underlined: Results]
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis | http://www.ahrq.gov/research/findings/evidence-based-reports/search.html; Search: prostate cancer AND proton therapy | 0
CADTH | https://www.cadth.ca; Search: prostate cancer AND proton therapy | 0
ECRI Institute | https://guidelines.ecri.org/; Search: prostate cancer AND proton therapy; Sanda MG, Chen RC, Crispino T, Freedland S, Greene K, Klotz LH, Makarov DV, Nelson JB, Reston J, Rodrigues G, Sandler HM, Taplin ME, Cadeddu JA. Clinically localized prostate cancer: AUA/ASTRO/SUO guideline (https://www.auanet.org/guidelines/guidelines/prostate-cancer-clinically-localized-guideline). Linthicum (MD): American Urological Association Education and Research, Inc.; 2017 Apr. 56 p. [283 references] | 1
HTA: Health Technology Assessments (UP TO 2016) | http://www.ohsu.edu/xd/education/library/; See CDSR search above | 0
NHS Evidence | http://www.evidence.nhs.uk/default.aspx; Search: prostate cancer AND proton therapy; Hayes, Inc. Proton beam therapy for prostate cancer (https://www.crd.york.ac.uk/crdweb/Showrecord.asp?LinkFrom=OAI&ID=32016000985&LinkFrom=OAI&ID=32016000985). 2016.; World Health Organization. WHO list of priority medical devices for cancer management (https://apps.who.int/iris/bitstream/handle/10665/255262/9789241565462-eng.pdf;jsessionid=5DAE45B64D7D106D8719D118F3BC9757?sequence=1). 2017. | 2
EPPI-Centre | http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62; Use browser search function [CNTL + F] for keyword search; Search: prostate cancer; proton therapy | 0
NLM | http://www.ncbi.nlm.nih.gov/books; Search: prostate cancer AND proton therapy; AHRQ. Therapies for Clinically Localized Prostate Cancer (https://www.ncbi.nlm.nih.gov/books/NBK562484/?term=prostate%20cancer%20AND%20proton%20therapy). 2020. | 1
VA Products - VATAP, PBM and HSR&D publications | A. http://www.hsrd.research.va.gov/research/default.cfm; B. http://www.research.va.gov/research_topics/; C. https://va.dimensions.ai/discover/publication; Search: prostate cancer AND proton therapy | 0

Search for systematic reviews currently under development (includes forthcoming reviews & protocols); Date Searched: 02-07-22
D. Under development | Evidence | Results
PROSPERO (SR registry) | http://www.crd.york.ac.uk/PROSPERO/; Search: prostate cancer AND proton therapy; Miloslav Klugar, Jitka Klugarová, Radim Líčeník, Zuzana Kelnarová, Andrea Pokorná, Ondřej Májek, Martin Doležel, Marek Babjuk, Vlastimil Válek, Karel Odrážka, Ladislav Dušek. Effectiveness of proton therapy in comparison with other types of radiation therapy in prostate cancer: a rapid review. PROSPERO 2019 CRD42019125204 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42019125204; Miloslav Klugar, Jitka Klugarová, Radim Líčeník, Zuzana Kelnarová, Andrea Pokorná, Ondřej Májek, Martin Doležel, Marek Babjuk, Vlastimil Válek, Karel Odrážka, Ladislav Dušek. Effectiveness of proton therapy in comparison with standard and other types of radiation therapy in prostate cancer: umbrella review. PROSPERO 2019 CRD42019125202 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42019125202; Lina Wang, Xiaohu Wang, Juntao Ran, Qiuning Zhang, Xiaoming Hou, Guangwen Zhang, Yichao Geng, Shuangwu Feng, Xueshan Zhao, Chengcheng Li. Efficacy and toxicity of carbon ion therapy or proton therapy for prostate cancer: a systematic review and meta-analysis. PROSPERO 2020 CRD42020148933 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020148933 | 3

#### PRIMARY STUDIES

Search for primary literature; Date searched: 02-09-22
MEDLINE [Ovid MEDLINE(R) ALL 1946 to February 08, 2022]
# | Search Statement | Results
[underlined: 1] | exp Prostatic Neoplasms/ OR (prostate neoplasm$1 OR prostate cancer$1 OR prostatic cancer$1 OR prostatic neoplasm$1).ti,ab. | 173681
[underlined: 2] | Protons/ OR Proton Therapy/ OR (proton* OR (proton adj2 therap*)).ti,ab. | 159712
[underlined: 3] | 1 AND 2 | 1077
4 | limit 3 to English language and yr=“2015-current” | 444
CINAHL
# | Search Statement | Results
1 | (MH “Prostatic Neoplasms+”) | 33515
2 | TI ( prostate neoplasm$1 OR prostate cancer$1 OR prostatic cancer$1 OR prostatic neoplasm$1 ) OR AB ( prostate neoplasm$1 OR prostate cancer$1 OR prostatic cancer$1 OR prostatic neoplasm$1 ) | 58
3 | 1 OR 2 | 33528
4 | (MH “Proton Therapy”) OR (MH “Protons”) | 2347
5 | TI (proton N2 therap*)) OR AB (proton N2 therap*)) | 2417
6 | 4 OR 5 | 3662
7 | 3 AND 6 | 258
8 | limit 7 to English language and yr=“2015-Current” | 108

### APPENDIX B SCIENTIFIC INFORMATION PACKET (SIP) REQUESTS

#### REQUESTED INFORMATION FROM MANUFACTURERS AND VENDORS

Data collection: Please describe your Center’s standard data collection mechanisms.

Published studies: Please provide a list of all published studies that meet our review inclusion criteria for population, intervention, comparison, outcome, and study design. In the list, indicate whether the protocol and results are available on ClinicalTrials.gov along with the ClinicalTrials.gov trial number.

Unpublished studies: Please also provide a list of all unpublished studies that meet our review inclusion criteria for population, intervention, comparison, outcome, and study design. For these, we ask that you submit a summary that includes the following elements: internal study number, ClinicalTrials.gov trial number where applicable, study dates, location, design, indication and diagnosis, inclusion and exclusion criteria, primary and secondary outcomes, patient population description, baseline characteristics (demographics and important prognostic characteristics), number of patients screened/eligible/enrolled/lost to follow-up/withdrawn/analyzed, effectiveness/efficacy, and safety results. In order for us to include data from unpublished studies, however, you also must submit a sufficient amount of detail on their methods to allow for adequate assessment of study quality using the criteria listed below. Data that does not meet these requirements may not be included in the report.

Quality assessment criteria for controlled trials:

- Was the assignment to the treatment groups really random?
- Was the treatment allocation concealed?
- Were the groups similar at baseline in terms of prognostic factors?
- Were the eligibility criteria specified?
- Were outcome assessors blinded to the treatment allocation?
- Was the care provider blinded?
- Was the patient kept unaware of the treatment received?
- Was an intention-to-treat (ITT) analysis conducted, or was data provided from which ITT results could be calculated (ie, number assigned to each group, number of subjects who finished in each group, and their results)?
- Did the study maintain comparable groups? Were there post-randomization exclusions of patients with specific characteristics?
- Was attrition, crossovers, adherence, and/or contamination reported?
- Was there differential loss to follow-up or overall high loss to follow-up?
- Quality assessment criteria for non-randomized studies (observational studies)
- Was the selection of patients for inclusion non-biased (Was any group of patients systematically excluded)? For cohort studies, was an inception cohort identified?
- Was there important differential loss to follow-up or overall high loss to follow-up?
- Were the patient outcomes specified and defined prior to the start of data collection?
- Was there a clear description of the techniques used to identify the outcomes?
- Was there non-biased and accurate ascertainment of outcomes (independent ascertainers; validation of ascertainment technique)?
- Were potential confounding variables and risk factors identified and examined using acceptable statistical techniques?
- Did the duration of follow-up correlate to reasonable timing for investigated events?

Unpublished, supplemental data for published studies. Examples of this include additional detail about study methods, additional outcomes, and results of additional subgroup analyses that did not appear in the publication.

A list of ongoing studies your company has sponsored for this indication. In the list, please provide the ClinicalTrials.gov trial number or, if the trial is not registered, the protocol for the study including a study number, the study period, design, methodology, indication and diagnosis, proper use instructions, inclusion and exclusion criteria, and primary and secondary outcomes.

Description of whether the above studies constitute ALL Phase II and above clinical trials sponsored by your company for this indication and an index outlining the relevant information in each submitted file.

#### MANUFACTURERS AND VENDORS CONTACTED

Company | Contact Info | Response
Hitachi | Phone: +1 408 986-6300; Research & Development US Headquarters (http://www.hitachi-america.us/rd/); Phone: (650) 244-7400; 2535 Augustine Dr, 3rd Floor, Santa Clara, CA 95054, USA | n/a
IBA Strategic Marketing (Ion Beam Applications) | info-worldwide@iba-group.com | n/a
Mevion Medical Systems | Email: research@mevion.com; Americas & Headquarters; 300 Foster St; Littleton, MA 01460, USA; Phone: +1 978 540-1500; Fax: +1 978 540-1501 | n/a
Sumitomo Heavy Industries | Industrial Equipment Division; Phone: +81-(0)3-6737-2565 or +81-(0)6-7635-3629; USA Office; 1833 Vultee St; Allentown, PA 18103, USA; Phone: +1 610 791-6700; Fax: +1 610 791-0440 | n/a
Varian Medical Systems | Michael Davis, MS, JD, Director, Research, & Educational Grants; Email: michael.davis@varian.com; Camille Noel, MSCI, PhD, Medical Science Liaison; Email: camille.noel@varian.com; Raymond Schulz, MSc, Clinical & Publications Manager; Email: raymond.schulz@varian.com | n/a
ProNova Solutions (Provision Healthcare) | Phone: +1 865 862-4112; Pronova Solutions; 330 Pellissippi Place; Maryville, TN 37804, USA; Phone: +1 865 862-4100 | Referred to Provision Cares Proton Therapy Center.
Optivus Proton Therapy | Corporate Office; Optivus Proton Therapy, Inc.; Phone: +1 909 799-8300; 1475 South Victoria Court; San Bernardino, CA 92408, USA | n/a
ProTom International | Sales & Development; 610 Parker Square; Flower Mound, TX 75028, USA; Email: info@protominternational.com; Cheryl Smith, VP, Administration; csmith@protominternational.com | n/a

### APPENDIX C EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible intervention, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design, 7=Ineligible publication type, 8=Outdated or ineligible systematic review.

Citation | Exclude Reason
Bai X, Lim G, Grosshans D, Mohan R, Cao W. Robust optimization to reduce the impact of biological effect variation from physical uncertainties in intensity-modulated proton therapy. Physics in Medicine & Biology. 2019;64(2):025004.30523932 30523932 | E6
Beckmann K, Garmo H, Nilsson P, Franck Lissbrant I, Widmark A, Stattin P. Radical radiotherapy for prostate cancer: patterns of care in Sweden 1998-2016. Acta Oncologica. 2020;59(5):549–557.32122185 | E4
Borowicz DM, Shipulin KN, Mytsin GV, . Ultra-Hypofractionated Proton Therapy in Localized Prostate Cancer: Passive Scattering versus Intensity-Modulated Proton Therapy. Journal of Personalized Medicine. 2021;11(12):06. | E4
Bryant CM, Henderson RH, Nichols RC, . Consensus Statement on Proton Therapy for Prostate Cancer. International Journal of Particle Therapy. 2021;8(2):1–16. | E7
Bryant CM, Hoppe BS. Promising long-term results with proton therapy for localized prostate cancer. Nature Reviews Urology. 2021;18(3):137–138. | E7
Choo R, Hillman DW, Daniels T, . Proton Therapy of Prostate and Pelvic Lymph Nodes for High Risk Prostate Cancer: Acute Toxicity. International Journal of Particle Therapy. 2021;8(2):41–50.34722810 | E6
Chung C, Yock T, Nelson K, Xu Y, Keating N, Tarbell N. Incidence of Second Malignancies Among Patients Treated with Proton versus Photon Radiation. International Journal of Radiation Oncology, Biology, Physics. 2013;87(1). | E3
Chuong MD, Hartsell W, Larson G, . Minimal toxicity after proton beam therapy for prostate and pelvic nodal irradiation: results from the proton collaborative group REG001-09 trial. Acta Oncologica. 2018;57(3):368–374.29034790 | E6
Coen JJ, Paly JJ, Niemierko A, . Long-Term Quality of Life Outcome After Proton Beam Monotherapy for Localized Prostate Cancer. International Journal of Radiation Oncology*Biology*Physics. 2012a;82(2):e201–e209.21621343 | E6
Cuaron JJ, Harris AA, Chon B, . Anterior-oriented proton beams for prostate cancer: A multi-institutional experience. Acta Oncologica. 2015;54(6):868–874.25591937 | E6
Deville Jr C, Jain A, Wei-Ting H, . Initial report of the genitourinary and gastrointestinal toxicity of postprostatectomy proton therapy for prostate cancer patients undergoing adjuvant or salvage radiotherapy. Acta Oncologica. 2018;57(11):1506–1514.30028227 | E6
Duttenhaver JA, Shipley WU, Perrone T, . Protons or megavoltage X-rays as boost therapy for patients irradiated for localized prostatic carcinoma an early phase I/II comparison. Cancer. 1983;51(9):1599–1604 6299503 | E4
Efstathiou JA, Kamran SC, Spratt DE. Protons Versus Photons for Prostate Cancer: An Answer That Is Long Overdue and Coming. International Journal of Radiation Oncology, Biology, Physics. 2021;110(4):1098–1100.34171235 | E7
Galbraith ME, Ramirez JM, Pedro LW. Quality of life, health outcomes, and identity for patients with prostate cancer in five different treatment groups. Oncology nursing forum. 2001;28(3):551–560.11338762 | E3
Habl G, Uhl M, Katayama S, . Acute Toxicity and Quality of Life in Patients With Prostate Cancer Treated With Protons or Carbon Ions in a Prospective Randomized Phase II Study--The IPI Trial. International Journal of Radiation Oncology, Biology, Physics. 2016;95(1):435–443.27084659 | E3
Haque W, Butler EB, Teh BS. Stereotactic body radiation therapy for prostate cancer-a review. Chinese Clinical Oncology. 2017;6(Suppl 2):S10.28917248 | E2
Holtzman AL, Hoppe BS, Letter HP, . Proton Therapy as Salvage Treatment for Local Relapse of Prostate Cancer Following Cryosurgery or High-Intensity Focused Ultrasound. International Journal of Radiation Oncology, Biology, Physics. 2016;95(1):465–471.26883560 | E6
Hoppe BS, Bryant C, Sandler HM. Radiation for Prostate Cancer: Intensity Modulated Radiation Therapy versus Proton Beam. The Journal of urology. 2015;193(4):1089–1091.25598137 | E7
Jagt TZ, Breedveld S, van Haveren R, Heijmen BJM, Hoogeman MS. Online-adaptive versus robust IMPT for prostate cancer: How much can we gain? Radiotherapy & Oncology. 2020;151:228–233.32777242 | E4
Kaiser A, Eley JG, Onyeuku NE, . Proton Therapy Delivery and Its Clinical Application in Select Solid Tumor Malignancies. Journal of Visualized Experiments. 2019;144(02):06. | E7
Kamran SC, McClatchy DM, 3rd, Pursley J, . Characterization of an Iodinated Rectal Spacer for Prostate Photon and Proton Radiation Therapy. Practical Radiation Oncology. 2021;05:05. | E7
Khmelevsky EV, Kancheli IN, Khoroshkov VS, Kaprin AD. Morbidity dynamics in proton-photon or photon radiation therapy for locally advanced prostate cancer. Reports of Practical Oncology & Radiotherapy. 2018;23(1):21–27.29204106 | E4
Kim E, Jang WI, Kim MS, . Clinical utilization of radiation therapy in Korea, 2016. Journal of Radiation Research. 2020;61(2):249–256.31913473 | E4
Kirk ML, Tang S, Zhai H, . Comparison of prostate proton treatment planning technique, interfraction robustness, and analysis of single-field treatment feasibility. Practical Radiation Oncology. 2015;5(2):99–105.25413411 | E4
Koerber SA, Katayama S, Sander A, . Prostate bed irradiation with alternative radio-oncological approaches (PAROS) - a prospective, multicenter and randomized phase III trial. Radiation Oncology. 2019;14(1):122.31291969 | E7
Kole TP, Nichols RC, Lei S, . A dosimetric comparison of ultra-hypofractionated passively scattered proton radiotherapy and stereotactic body radiotherapy (SBRT) in the definitive treatment of localized prostate cancer. Acta Oncologica. 2015;54(6):825–31.25227898 | E4
Konski A, Speier W, Hanlon A, Beck JR, Pollack A. Is Proton Beam Therapy Cost Effective in the Treatment of Adenocarcinoma of the Prostate? Journal of Clinical Oncology. 2007;25(24):3603–3608.17704408 | E6
Kowalchuk RO, Hillman D, Daniels TB, . Assessing concordance between patient-reported and investigator-reported CTCAE after proton beam therapy for prostate cancer. Clinical and Translational Radiation Oncology. 2021;31:34–41.34604551 | E4
Lee HJ, Macomber MW, Spraker MB, . Early toxicity and patient reported quality-of-life in patients receiving proton therapy for localized prostate cancer: a single institutional review of prospectively recorded outcomes. Radiation Oncology. 2018;13(1):. | E6
Lee WR. Proton-beam therapy after radical prostatectomy: Continued DVH idolatry? Cancer. 2019;125(23):4136–4138.31503326 | E7
Li M, Li X, Yao L, . Clinical Efficacy and Safety of Proton and Carbon Ion Radiotherapy for Prostate Cancer: A Systematic Review and Meta-Analysis. In. Frontiers in Oncology. Vol 11 2021:709530.34712607 | E8
Lockney NA, Henderson RH, Swarts SG, . Measuring Radiation Toxicity Using Circulating Cell-Free DNA in Prostate Cancer Patients. International Journal of Particle Therapy. 2022;8(3):28–35.35127973 | E4
Lockney NA, Zhang M, Morris CG, . Radiation-induced tumor immunity in patients with non-small cell lung cancer. Thoracic Cancer. 2019;10(7):1605–1611.31228354 | E1
Ma D, Bronk L, Kerr M, . Exploring the advantages of intensity-modulated proton therapy: experimental validation of biological effects using two different beam intensity-modulation patterns. Scientific Reports. 2020;10(1):3199.32081928 | E6
Maeda Y, Sato Y, Shibata S, . Effects of organ motion on proton prostate treatments, as determined from analysis of daily CT imaging for patient positioning. Medical Physics. 2018;45(5):1844–1856.29574901 | E4
Maeda Y, Sato Y, Yamamoto K, . Stability of daily rectal movement and effectiveness of replanning protocols for sparing rectal doses based on the daily CT images during proton treatment for prostate cancer. Journal of Applied Clinical Medical Physics. 2020;21(10):109–121. | E4
Manganaro L, Attili A, Bortfeld T, Paganetti H. Spatiotemporal optimisation of prostate intensity modulated proton therapy (IMPT) treatments. Physics in Medicine & Biology. 2022;27:27. | E4
Marteinsdottir M, Paganetti H. Applying a variable relative biological effectiveness (RBE) might affect the analysis of clinical trials comparing photon and proton therapy for prostate cancer. Physics in Medicine & Biology. 2019;64(11):115027.31082810 | E4
Matsukawa K, Arimura T, Orita M, . Health-related quality of life in Japanese patients with prostate cancer following proton beam therapy: an institutional cohort study. Japanese Journal of Clinical Oncology. 2020;50(5):519–527.32129447 | E6
Mayer EN, Tward JD, Bassett M, . Management of Radiation Therapy Oncology Group grade 4 urinary adverse events after radiotherapy for prostate cancer. BJU International. 2017;119(5):700–708.27469289 | E2
Mendenhall WM, Glassman G, Morris CG, . Bacterial Urinary Tract Infection after Transrectal Placement of Fiducial Markers prior to Proton Radiotherapy for Prostate Cancer. International Journal of Particle Therapy. 2016;3(1):21–26.31772972 | E6
Moteabbed M, Harisinghani M, Paganetti H, Trofimov A, Lu HM, Efstathiou JA. Proton vs. photon radiotherapy for MR-guided dose escalation of intraprostatic lesions. Acta Oncologica. 2021;60(10):1283–1290.34282708 | E4
Moteabbed M, Trofimov A, Khan FH, . Impact of interfractional motion on hypofractionated pencil beam scanning proton therapy and VMAT delivery for prostate cancer. Medical Physics. 2018;14:14. | E4
Moteabbed M, Trofimov A, Sharp GC, . A Prospective Comparison of the Effects of Interfractional Variations on Proton Therapy and Intensity Modulated Radiation Therapy for Prostate Cancer. International Journal of Radiation Oncology, Biology, Physics. 2016;95(1):444–453.26907917 | E4
Narter F. Re: A Literature Review of Proton Beam Therapy for Prostate Cancer in Japan. Journal of Urological Surgery. 2019;6(1):81–81. | E7
Nichols RC, Morris CG, Bryant C, . Serum Testosterone 60 Months after Passive-Scatter Proton Therapy for Localized Prostate Cancer. Cancer Investigation. 2019;37(2):85–89.30836776 | E6
Nihei K, Ogino T, Onozawa M, . Multi-institutional Phase II study of proton beam therapy for organ-confined prostate cancer focusing on the incidence of late rectal toxicities. Int J Radiat Oncol Biol Phys. 2011;81(2):390–396.20832180 | E6
Ontario H. Proton Beam Therapy for Cancer in Children and Adults: A Health Technology Assessment. In. Ontario Health Technology Assessment Series. Vol 21 2021:1–142. | E8
Paganetti H. Relating the proton relative biological effectiveness to tumor control and normal tissue complication probabilities assuming interpatient variability in alpha/beta. Acta Oncologica. 2017;56(11):1379–1386.28918679 | E6
Paganetti H, Giantsoudi D. Relative Biological Effectiveness Uncertainties and Implications for Beam Arrangements and Dose Constraints in Proton Therapy. Seminars in Radiation Oncology. 2018;28(3):256–263.29933885 | E7
Pan HY, Jiang J, Shih YT, Smith BD. Adoption of Radiation Technology Among Privately Insured Nonelderly Patients With Cancer in the United States, 2008 to 2014: A Claims-Based Analysis. Journal of the American College of Radiology. 2017;14(8):1027–1033.e2.28408078 | E4
Pang EPP, Knight K, Park SY, . Duration-dependent margins for prostate radiotherapy-a practical motion mitigation strategy. Strahlentherapie und Onkologie. 2020;196(7):657–663.31932995 | E4
Parthan A, Pruttivarasin N, Davies D, . Comparative Cost-Effectiveness of Stereotactic Body Radiation Therapy Versus Intensity-Modulated and Proton Radiation Therapy for Localized Prostate Cancer. Frontiers in Oncology. 2012;2. | E6
Pedersen J, Liang X, Bryant C, Mendenhall N, Li Z, Muren LP. Normal tissue complication probability models for prospectively scored late rectal and urinary morbidity after proton therapy of prostate cancer. Physics & Imaging in Radiation Oncology. 2021;20:62–68.34805558 | E4
Pedersen J, Liang X, Casares-Magaz O, . Multivariate normal tissue complication probability models for rectal and bladder morbidity in prostate cancer patients treated with proton therapy. Radiotherapy & Oncology. 2020;153:279–288.33096166 | E4
Pollack A, Zagars GK, Starkschall G, . Prostate cancer radiation dose response: results of the M. D. Anderson phase III randomized trial. Int J Radiat Oncol Biol Phys. 2002;53(5):1097–105.12128107 | E2
Pugh TJ, Choi S, Nogueras-Gonzalaez GM, . Proton Beam Therapy for Localized Prostate Cancer: Results from a Prospective Quality-of-Life Trial. International Journal of Particle Therapy. 2016;3(1):27–36.31772973 | E6
Quinn TJ, Hamstra D. Hypofractionation in Prostate Cancer Using Proton Beam. International Journal of Radiation Oncology, Biology, Physics. 2019;105(4):723–726.31655657 | E7
Ricco A, Hanlon A, Lanciano R. Propensity Score Matched Comparison of Intensity Modulated Radiation Therapy vs Stereotactic Body Radiation Therapy for Localized Prostate Cancer: A Survival Analysis from the National Cancer Database. Frontiers in Oncology. 2017;7:185.28913176 | E2
Sandler H. Reply by Author. Journal of Urology. 2015;194(5):1508–9. | E7
Schulz-Ertner D, Tsujii H. Particle Radiation Therapy Using Proton and Heavier Ion Beams. Journal of Clinical Oncology. 2007;25(8):953–964.17350944 | E7
Schwarz M, Molinelli S. What can particle therapy add to the treatment of prostate cancer? Physica Medica. 2016;32(3):485–91.27061870 | E7
Shipley WU, Verhey LJ, Munzenrider JE, . Advanced prostate cancer: The results of a randomized comparative trial of high dose irradiation boosting with conformal protons compared with conventional dose irradiation using photons alone. International journal of radiation oncology, biology, physics. 1995;32(1):3–12.7721636 | E3
Sidaway P. Prostate cancer: Proton therapy delays progression. Nature Reviews Urology. 2016;13(4):181. | E7
Slater JM, Slater JD, Kang JI, . Hypofractionated Proton Therapy in Early Prostate Cancer: Results of a Phase I/II Trial at Loma Linda University. International Journal of Particle Therapy. 2019;6(1):1–9. | E6
Taneja SS. Re: Five-Year Biochemical Results, Toxicity, and Patient-Reported Quality of Life after Delivery of Dose-Escalated Image Guided Proton Therapy for Prostate Cancer. Journal of Urology. 2017;197(1):149–152.27979505 | E7
Tang C, Lei X, Smith GL, . Influence of Geography on Prostate Cancer Treatment. International Journal of Radiation Oncology, Biology, Physics. 2021;109(5):1286–1295.33316361 | E4
Thompson AB, Hamstra DA. Rectal Spacer Usage with Proton Radiation Therapy for Prostate Cancer. International Journal of Radiation Oncology, Biology, Physics. 2020;108(3):644–648.32976788 | E7
Tung CJ. Proton therapy. Biomedical Journal. 2015;38(5):389–90.26459791 | E7
Vapiwala N. Re: Radiation for Prostate Cancer: Intensity Modulated Radiation Therapy versus Proton Beam: B. S. Hoppe, C. Bryant and H. M. Sandler. J Urol 2015;193:1089–1091. Journal of Urology. 2015;194(5):1507-8.25598137 | E7
Vargas CE, Hartsell WF, Dunn M, . Image-guided hypofractionated proton beam therapy for low-risk prostate cancer: Analysis of quality of life and toxicity, PCG GU 002. Reports of Practical Oncology & Radiotherapy. 2016;21(3):207–212.27601952 | E6
Verma V, Simone CB, 2nd, Mishra MV. Quality of Life and Patient-Reported Outcomes Following Proton Radiation Therapy: A Systematic Review. Journal of the National Cancer Institute. 2018;110(4):01. | E8
Wolf MB, Edler C, Tichy D, . Diffusion-weighted MRI treatment monitoring of primary hypofractionated proton and carbon ion prostate cancer irradiation using raster scan technique. Journal of Magnetic Resonance Imaging. 2017;46(3):850–860.28152251 | E6
Yang Y, Vargas CE, Bhangoo RS, . Exploratory Investigation of Dose-Linear Energy Transfer (LET) Volume Histogram (DLVH) for Adverse Events Study in Intensity Modulated Proton Therapy (IMPT). International Journal of Radiation Oncology, Biology, Physics. 2021;110(4):1189–1199.33621660 | E4
Zietman AL. Can proton therapy be considered a standard of care in oncology? Lessons from the United States. British Journal of Cancer. 2019;120(8):775–776.30911089 | E7

### APPENDIX D EVIDENCE TABLES

#### CHARACTERISTICS OF INCLUDED COMPARATIVE STUDIES

#### CHARACTERISTICS OF INCLUDED NONCOMPARATIVE STUDIES WITH SUBGROUPS

#### OUTCOME DATA OF INCLUDED COMPARATIVE STUDIES

#### OUTCOME DATA OF INCLUDED NONCOMPARATIVE STUDIES WITH SUBGROUPS

#### QUALITY ASSESSMENT OF INCLUDED PRIMARY STUDIES

Observational Studies (Rated with ROBINS-I for Observational Studies)

#### STRENGTH OF EVIDENCE

Conclusions Derived from Comparative Studies Having Low Risk of Bias

### APPENDIX E PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you for your feedback.
2 | 2 | Yes | Thank you for your feedback.
4 | 4 | Yes | Thank you for your feedback.
5 | 5 | Yes | Thank you for your feedback.
Is there any indication of bias in our synthesis of the evidence?
6 | 1 | No | Thank you for your feedback.
7 | 2 | Yes – Assumption was made that external beam techniques have improved over time, but that proton techniques have not. Thus older data from protons is acceptable, but not older data from photons (although not consistently applied throughout the whole process). | The issue of evolution of proton therapeutic techniques is addressed in the section on technological issues on page 23.
8 | 2 | Yes - Key question one ask for differences in benefits and HARMS between treatments. Second malignancies were mentioned as one of the “potential harms” for comparison, but then were not evaluated in the literature review. | We added a section to the Results section regarding evidence about second malignancies.
9 | 4 | No | Thank you for your feedback.
10 | 5 | No | Thank you for your feedback.
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
11 | 1 | No
12 | 2 | Yes - Xiang M, Chang DT, Pollom EL. Second cancer risk after primary cancer treatment with three-dimennsional conformal, intensity-modulated, or proton beam radiation therapy. Cancer 2020, 126:3560–3568.32426866; NCDB evaluation of second malignancies for different modalities; prostate cancer showed the greatest difference between protons and IMRT/3-D of any of the 9 tumor types, statistically very significant. | Thank you for this identifying this citation; we have reviewed it and added it to our report.
13 | 4 | No | Thank you for your feedback
14 | 5 | No | Thank you for your feedback
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
15 | 1 | Table ES, page 3. Suggest adding “…with PBT” after “Patients with worse baseline risk assessments experienced higher rates of cancer recurrence over time”. | Thank you. This change was made.
16 | 2 | Overall, this is an excellent review of the current literature on PBT vs IMRT/3-D. There are a few gaps which could be filled in to make this a make complete assessment. As was stated in the report, there will be significantly more high quality data in the next few years with completion and publication of the prospective comparative trials. | Thank you for your feedback; we have addressed your individual comments as noted below.
17 | 2 | Executive summary; No mention of second malignancy rates (although mentioned on page 8); Primary differences would be expected in decreased side effects, not in tumor control (this is the ALARA principle – we reduce the total body exposure for imaging because of risks, not taken into consideration here for differences in treatment) | A section on second malignancies for the PBT vs IMRT comparison has been added to the Strength of Evidence table.
18 | 2 | Page 9; Studies comparing PBT to older techniques were excluded – were studies comparing older techniques of PBT excluded? There has been a change in PBT technology and techniques as well. | The included studies all were published after 2010 and generally included only patients who were initially diagnosed with prostate cancer after 2000. This clarification was added to the first paragraph of the Literature Overview section on page 14.
19 | 2 | P14-15; Most of these studies did not control for dose, which is very highly correlated with GI and GU toxicity (eg, Sheets and Yu). Coen study – most of “proton” patients only received 36% of dose with protons, the majority with photons | Dosage ranges are included in the summary of the comparative studies in Table 1. The problem of proton dosage in the Coen study is also now addressed in the section on brachytherapy on p. 22.
20 | 2 | Page 19; 10-year survival was superior in the PBT group (80.1%) than in IMRT/3-D group (71.3%), but was called “significantly lower” for the PBT group. Evidence is called inconclusive because the number of IMRT vs 3-D patients in the external beam group is not defined. This treats PBT as though there has been no change in planning or treatment processes during this time period. This is using “historical treatment bias” in one group but not the other… | Thank you for catching this typographical error regarding survival rates. The sentence was corrected. The identified study (Liu et al. Clin Genitourin Cancer 2021;19:255-66) included patients treated between 2004 and 2015. It grouped the patients receiving IMRT or 3-dimension conformal radiotherapy (3DCRT) into a single group and provided no data comparing the IMRT and 3DCRT sub-groups. Thus, it is not possible to determine whether there were differences in the dates of treatment between the IMRT and 3DCRT sub-groups. A new sentence was added to this paragraph to clarify these issues.
21 | 2 | Page 19; Next paragraph compares protons to brachytherapy, showing no difference in survival. Please evaluate evidence for second malignancies for these two comparisons – PBT and brachytherapy have lower risks of 2nd malignancies compared to IMRT/3-D, at least should be considered as one of the differences between the treatments | We identified no studies comparing PBT to brachytherapy for any toxicity, including second cancer incidence. This lack of evidence is now called out in the summary.
22 | 2 | Xiang M, Chang DT, Pollom EL. Second cancer risk after primary cancer treatment with three-dimennsional conformal, intensity-modulated, or proton beam radiation therapy. Cancer 2020, 126:3560–3568.32426866 | Thank you for this citation, we have reviewed it and added it to our report.
23 | 4 | Excellent manuscript - well written with comprehensive references. | Thank you for your comment.
24 | 5 | Page/line: 4/9: “individualized decision” - probably should be changed. Within the VA, there are limitations to resources and referrals, and the decision may not be individualized pending local/VA policy. It could be substituted to a “complex” or “nuanced”. | Thank you. This change was made.
25 | 5 | Page/line: 5/39: “anatomical structures including nerves, the urethra, and the rectum”. With regard to notable anatomic structures, the bladder is a critical one with significant effects on GU toxicity. Perhaps “nerves, the bladder, the urethra and the rectum” | Thank you. This change was made.
26 | 5 | Page/line: 5/48: “high-intensity photons”. Please change to “high-energy”; the intensity is not the basis of the radiation therapy. For example, dermatologists utilize UV and light therapy which is also “intense photons” but not “high-energy” like megavoltage photons. | Thank you. This change was made.
27 | 5 | Page/line: 6/7: “and stereotactic radiosurgery (SRS)” - should be changed to “stereotactic ablative body radiation (SABR)”. SRS is a technique specifically for the brain (as termed within radiation oncology). SABR is another name for SBRT | Thank you. These wording changes were made.
28 | 5 | Page/line: 6/11: “with several dozen treatment sessions” - should be changed to “few dozen”. The longest treatment duration for prostate cancer (within the modern standard of care) is 44-45 fractions of daily radiation, and few dozen (meaning up to 4 dozen) should suffice. Several dozen implies many months of radiation therapy. | Thank you. This change was made.
29 | 5 | Page/line: 8/45: “Potential Harms”. Would it be worthwhile to include “financial cost” (or something like “socioeconomic factors”)? Proton beam therapy is typically considerably more expensive than photon radiation, and patients may experience excessive costs/financial toxicity with regards to it. As there are less proton centers in the US as well, the costs of transportation are often sizeable. | Thank you. These issues were added to the Analytic Framework.
30 | 5 | Page/line: 16/14: “Rates of early GU toxicity ranged from 0 to 45%…”. This statement/data are generated from the studies, but they do differ from traditional estimates of the IMRT toxicity, and may subsequently decrease the comparative benefit. Since the proton-photon benefit, while consistently cited, is small - would it be worthwhile to explore the consistency of these reported IMRT GU toxicity rates with at least one meta-analysis from IMRT GU toxicity in general? The Vapiwala 2021 early GU toxicity study seems to have an outsized risk ratio of 0.06 (an ORDER OF MAGNITUDE different (the other two are 0.62 and 0.74 versus Vapiwala’s 0.06) versus the other two studies on page 17). Similarly, the late GU toxicity in that study was defined by >3mo, which is in stark comparison to the others. | We agree with this concern and have extensively revised the meta-analyses to address it. The analysis now better stratifies by endpoint and improves comparability of estimates. The description of these analyses is now more extensive and addresses important issues regarding methodological variability in the primary studies (particularly in outcome definitions). As a result of these new analyses, the final Strength of Evidence assessment for GU toxicity was revised from Moderate to Low.
31 | 5 | Page/line: 19/8: “10-year survival rates were significantly lower in the PBT group (80.1%) than in the external beam photon group (71.3%)” - this is a typo and needs to be changed to “significantly HIGHER”. | Thank you. This change was made.
32 | 5 | Page/line: 20/52: “conventional forms of beam scanning” - this should be changed to “conventional proton beam therapy” (or similar). Conventional proton therapy (passive scattering) typically does not involve “beam scanning”. Proton PBS involves a thin “raster laser-like painting” of the target (in a scanning fashion, hence pencil beam scanning), while passive scattering creates a complex portal field, usually with physical compensators. | Thank you. This change was made.
33 | 5 | Page/line: 22/29: “Harms of any type of radiation therapy” - this should be changed to “any type of prostate-directed radiation therapy”. Patients who receive radiation therapy to the breast or brain (for example) will not experience appreciable or directly related GI/GU/sexual toxicity, as those organs are essentially untouched by the radiation. | Thank you. This change was made.
34 | 5 | Page/line: 22/34: “a series of adequately controlled”. This seems superficial (perhaps even specious). As there are no RCTs included in the analysis, this should be “adequately case-controlled” or “adequately compared”. The studies cited do not seem to include or utilize true controlling methodology, which would involve randomization or blinding | Thank you. This sentence has been re-written to clarify the methods used in the observational studies.
35 | 5 | Page/line: 24/28: “EarlyToxicity” - should be “Early Toxicity”. This is a typo of the reference | The title for this reference was corrected.

### APPENDIX F RESEARCH IN PROGRESS

Status | Study Title | Study Design | Information Resources
Studies with Comparator (eg, PBT vs Other Treatment)
Recruiting | Radiation Therapy (Hypofractionated Proton Beam Therapy or IMRT) for the Treatment of Recurrent, Oligometastatic Prostate Cancer Following Primary Localized Treatment | RCT | ClinicalTrials.gov ID: NCT04190446 (https://clinicaltrials.gov/ct2/show/NCT04190446?id=NCT04190446&draw=2&rank=1)
Recruiting | Prostate bed irradiation with alternative radio-oncological approaches | RCT | German Clinical Trials Register ID: DRKS00015231 (https://www.drks.de/drks_web/navigate.do?navigationId=trial.HTML&TRIAL_ID=DRKS00015231)
Recruiting | Prostate Advanced Radiation Technologies Investigating Quality of Life (PARTIQoL): A Phase III Randomized Clinical Trial of Proton Therapy vs IMRT for Low or Intermediate Risk Prostate Cancer | RCT | ClinicalTrials.gov ID: NCT01617161 (https://clinicaltrials.gov/ct2/show/NCT01617161)
Recruiting | Phase III Study of Image Guided Radiation Therapy with or Without Androgen Suppression for Intermediate Risk Adenocarcinoma of the Prostate | RCT | ClinicalTrials.gov ID: NCT01492972 (https://clinicaltrials.gov/ct2/show/NCT01492972?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=4&rank=25&load=cart)
Recruiting | A Prospective Comparative Study of Outcomes with Proton and Photon Radiation in Prostate Cancer | Prospective Cohort | ClinicalTrials.gov ID: NCT03561220 (https://clinicaltrials.gov/ct2/show/NCT03561220)
Recruiting | Prostate Cancer Patients Treated with Alternative Radiation Oncology Strategies | RCT | ClinicalTrials.gov ID: NCT04083937 (https://clinicaltrials.gov/ct2/show/NCT04083937?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=2&rank=8&load=cart)
Recruiting | Preference-based Comparative Study on Definitive Radiotherapy of Prostate Cancer with Protons in Standard Fractionation and Standard Dosage | Non-randomized Controlled Trial | ClinicalTrials.gov ID: NCT02766686 (https://clinicaltrials.gov/ct2/show/NCT02766686?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=3&rank=17&load=cart)
Active, not recruiting | A Phase II Trial of Proton Radiation Therapy or Intensity-modulated Radiation Therapy Using Mild Hypofractionation for Low- and Intermediate-risk Adenocarcinoma of the Prostate | Prospective Cohort | ClinicalTrials.gov ID: NCT01352429 (https://clinicaltrials.gov/ct2/show/NCT01352429?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=4&rank=28&load=cart)
Active, not recruiting | Proton-Based Stereotactic Ablative Body Radiotherapy for Prostate Cancer | Prospective Cohort | ClinicalTrials.gov ID: NCT03159676 (https://clinicaltrials.gov/ct2/show/NCT03159676?id=NCT03159676&draw=2&rank=1)
Studies without Other Treatment Comparator (eg, Case Series or Pre-Post Design)
Enrolling by Invitation | Assessing the Effectiveness of Photon Therapy with a Proton Therapy Boost in the Treatment of Prostate Cancer as Compared to Phone Therapy Alone | Case Series/ Uncontrolled Pre-Post Study | ClinicalTrials.gov ID: NCT03564275 (https://clinicaltrials.gov/ct2/show/NCT03564275?titles=Assessing+the+Effectiveness+of+Photon+Therapy+With+a+Proton+Therapy+Boost+in+the+Treatment+of+Prostate+Cancer+as+Compared+to+Photon+Therapy+Alone&draw=2&rank=1)
Recruiting | Phase II Study of Pencil Beam Scanning Proton Stereotactic Body Radiation Therapy for Prostate Cancer | Case Series/ Uncontrolled Pre-Post Study | ClinicalTrials.gov ID: NCT04842890 (https://clinicaltrials.gov/ct2/show/NCT04842890?id=NCT04842890&draw=2&rank=1)
Recruiting | Carbon Ion Boost Followed by Pelvic Proton Radiotherapy for Prostate Cancer with Pelvic Lymph Nodes Metastases: Prospective Phase II Study | Case Series/ Uncontrolled Pre-Post Study | ClinicalTrials.gov ID: NCT05106699 (https://clinicaltrials.gov/ct2/show/NCT05106699?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=2&rank=1&load=cart)
Recruiting | Extended-Field Lymph Node Proton Irradiation for High Risk Prostate Cancer | Case Series/ Uncontrolled Pre-Post Study | ClinicalTrials.gov ID: NCT04725903 (https://clinicaltrials.gov/ct2/show/NCT04725903?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=2&rank=4&load=cart)
Recruiting | “Spot-Scanning Based Hypofractionated Proton Therapy for Low and Intermediate Risk Prostate Cancer” “Hypofraktionierte Protonentherapie Mit Spot-Scanning-Technik Bei Prostatakarzinom Mit Niedrigem Oder Mittlerem Risiko” | Case Series/ Uncontrolled Pre-Post Study | ClinicalTrial.gov ID: NCT03740191 (https://clinicaltrials.gov/ct2/show/NCT03740191?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=2&rank=9&load=cart)
Recruiting | A Phase II Study of Dose-escalated Proton-based Radiation Therapy Delivered with a Simultaneous Integrated Boost (SIB) to Intraprostatic Tumors (IPT) Visible on Pretreatment Magnetic Resonance Image | Non-randomized Controlled Trial | ClinicalTrials.gov ID: NCT03624660 (https://clinicaltrials.gov/ct2/show/NCT03624660?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=2&rank=10&load=cart)
Recruiting | A Phase II Randomized Trial of Hypofractionated Proton Therapy in Patients with a Localized Prostate Adenocarcinoma | RCT | ClinicalTrials.gov ID: NCT03285815 (https://clinicaltrials.gov/ct2/show/NCT03285815?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=3&rank=13&load=cart)
Recruiting | A Phase II Study of Hypofractionated Image Guided Proton Therapy for Low and Intermediate Risk Prostate Cancer | Case Series/ Uncontrolled Pre-Post Study | ClinicalTrials.gov ID: NCT02040610 (https://clinicaltrials.gov/ct2/show/NCT02040610?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=3&rank=20&load=cart)
Active, not recruiting | A Phase II Study of Proton-Based Radiation Therapy with Elective Pelvic Nodal Irradiation, Concomitant Docetaxel, and Adjuvant Androgen Deprivation for High-risk Prostate Adenocarcinoma | Non-randomized Controlled Trial | ClinicalTrials.gov ID: NCT01040624 (https://clinicaltrials.gov/ct2/show/NCT01040624?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=5&rank=32&load=cart)
Active, not recruiting | Prospective Evaluation of Hypofractionation Proton Beam Therapy with Concurrent Treatment of the Prostate and Pelvic Nodes for Clinically Localized, High Risk or Unfavorable Intermediate Risk Prostate Cancer | Case Series/ Uncontrolled Pre-post Study | ClinicalTrials.gov ID: NCT02874014 (https://clinicaltrials.gov/ct2/show/NCT02874014?id=NCT02874014&draw=2&rank=1)
Active, not recruiting | Phase II Trial of Hypofractionated Proton Beam Therapy in Men with Localized Prostate Adenocarcinoma | Case Series/ Uncontrolled Pre-post Study | ClinicalTrials.gov ID: NCT01950351 (https://clinicaltrials.gov/ct2/show/NCT01950351?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=4&rank=21&load=cart)
Active, not recruiting | An Expanded Phase II Study of Hypofractionated Dose Intense Image Guided Proton Radiation Therapy for Low and Intermediate Risk Adenocarcinoma of the Prostate | Non-randomized Controlled Trial | ClinicalTrials.gov ID: NCT01368055 (https://clinicaltrials.gov/ct2/show/NCT01368055?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=4&rank=27&load=cart)
Active, not recruiting | A Phase III Prospective Randomized Trial of Standard-fractionation vs. Hypo-fractionation With Proton Radiation Therapy for Low Risk Adenocarcinoma of the Prostate | RCT | ClinicalTrials.gov ID: NCT01230866 (https://clinicaltrials.gov/ct2/show/NCT01230866?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=4&rank=29&load=cart)
Active, not recruiting | A Phase II Trial of Proton Radiation Therapy of Using Standard Fractionation for Low- and Low-intermediate Risk Adenocarcinoma of the Prostate | Case Series/ Uncontrolled Pre-post Study | ClinicalTrials.gov ID: NCT01045226 (https://clinicaltrials.gov/ct2/show/NCT01045226?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=5&rank=31&load=cart)
Active, not recruiting | A Phase II Study of Hypofractionated Image Guided Proton Radiation Therapy for Low and Intermediate Risk Adenocarcinoma of the Prostate | Non-randomized Controlled Trial | ClinicalTrials.gov ID: NCT00693238 (https://clinicaltrials.gov/ct2/show/NCT00693238?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=5&rank=34&load=cart)
Completed | Semen Analysis Following Definitive Treatment of Prostate Cancer with Proton Radiation Therapy Alone | Case Series/ Uncontrolled Pre-post Study | ClinicalTrials.gov ID: NCT01072513 (https://clinicaltrials.gov/ct2/show/NCT01072513?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=4&rank=30&load=cart)
Completed; No results posted | Proton Beam Radiation Therapy for Early Stage Adenocarcinoma of the Prostate | Case Series/ Uncontrolled Pre-post Study | ClinicalTrials.gov ID: NCT00585962 (https://clinicaltrials.gov/ct2/show/NCT00585962?id=NCT00585962&draw=2&rank=1)
Unknown | Prospective Evaluation of Quality of Life After Proton Therapy for Prostate Cancer | Prospective Cohort | ClinicalTrials.gov ID: NCT00489814 (https://clinicaltrials.gov/ct2/show/NCT00489814?id=NCT05106699+OR+NCT02040610+OR+NCT04842890+OR+NCT02874014+OR+NCT03740191+OR+NCT01230866+OR+NCT03561220+OR+NCT03564275+OR+NCT01709253+OR+NCT00489814+OR+NCT00585962+OR+NCT00693238+OR+NCT00831623+OR+NCT03624660+OR+NCT02766686+OR+NCT01040624+OR+NCT03285815+OR+NCT03159676+OR+NCT01950351+OR+NCT01072513+OR+NCT01368055+OR+NCT04725903+OR+NCT01617161+OR+NCT01045226+OR+NCT04190446+OR+NCT01352429+OR+NCT01492972+OR+NCT04083937+OR+NCT02935023+OR+NCT05010343+OR+NCT02739659+OR+NCT01478412+OR+NCT04724577+OR+NCT04486755+OR+NCT01859221+OR+NCT02315989&draw=9&rank=36&load=cart)

Abbreviations. IMRT=intensity modulated radiation therapy; IPT=intraprostatic tumors; RCT=randomized controlled trials; SIB=simultaneous integrated boost.

### REFERENCES

1 Bai M, Gergelis KR, Sir M, . Comparing bowel and urinary domains of patient-reported quality of life at the end of and 3 months post radiotherapy between intensity-modulated radiotherapy and proton beam therapy for clinically localized prostate cancer. Cancer Medicine. 2020;9(21):7925–7934.32931662
2 Barsky AR, Carmona R, Verma V, . Comparative Analysis of 5-Year Clinical Outcomes and Patterns of Failure of Proton Beam Therapy Versus Intensity Modulated Radiation therapy for Prostate Cancer in the Postoperative Setting. Practical Radiation Oncology. 2021;11(2):e195–e202.33242634
3 Coen JJMD, Zietman ALMD, Rossi CJMD, . Comparison of High-Dose Proton Radiotherapy and Brachytherapy in Localized Prostate Cancer: A Case-Matched Analysis. International journal of radiation oncology, biology, physics. 2012b;82(1):e25–e31.21470787
4 Dutz A, Agolli L, Baumann M, . Early and late side effects, dosimetric parameters and quality of life after proton beam therapy and IMRT for prostate cancer: a matched-pair analysis. Acta Oncologica. 2019;58(6):916–925.30882264
5 Fang P, Mick R, Deville C, . A case-matched study of toxicity outcomes after proton therapy and intensity-modulated radiation therapy for prostate cancer. Cancer. 2014;121(7):1118–1127.25423899
6 Gray PJ, Paly JJ, Yeap BY, . Patient-reported outcomes after 3-dimensional conformal, intensity-modulated, or proton beam radiotherapy for localized prostate cancer. Cancer. 2013;119(9):1729–1735.23436283
7 Halpern JA, Sedrakyan A, Hsu WC, . Use, complications, and costs of stereotactic body radiotherapy for localized prostate cancer. Cancer. 2016;122(16):2496–2504.27224858
8 Hoppe BS, Michalski JM, Mendenhall NP, . Comparative effectiveness study of patient-reported outcomes after proton therapy or intensity-modulated radiotherapy for prostate cancer. Cancer. 2014;120(7):1076–1082.24382757
9 Kim S, Shen S, Moore DF, . Late Gastrointestinal Toxicities Following Radiation Therapy for Prostate Cancer. European urology. 2011;60(5):908–916.21684064
10 Liu Y, Patel SA, Jani AB, . Overall Survival After Treatment of Localized Prostate Cancer With Proton Beam Therapy, External-Beam Photon Therapy, or Brachytherapy. Clinical Genitourinary Cancer. 2021;19(3):255–266.e257.32972877
11 Pan HY, Jiang J, Hoffman KE, . Comparative Toxicities and Cost of Intensity-Modulated Radiotherapy, Proton Radiation, and Stereotactic Body Radiotherapy Among Younger Men With Prostate Cancer. Journal of Clinical Oncology. 2018;36(18):1823–1830.29561693
12 Santos PMG, Barsky AR, Hwang WT, . Comparative toxicity outcomes of proton-beam therapy versus intensity-modulated radiotherapy for prostate cancer in the postoperative setting. Cancer. 2019;125(23):4278–4293.31503338
13 Sheets NC, Goldin GH, Meyer A-M, . Intensity-Modulated Radiation Therapy, Proton Therapy, or Conformal Radiation Therapy and Morbidity and Disease Control in Localized Prostate Cancer. JAMA : the Journal of the American Medical Association. 2012;307(15):1611–1620.22511689
14 Vapiwala N, Wong JK, Handorf E, . A Pooled Toxicity Analysis of Moderately Hypofractionated Proton Beam Therapy and Intensity Modulated Radiation Therapy in Early-Stage Prostate Cancer Patients. International Journal of Radiation Oncology, Biology, Physics. 2021;110(4):1082–1089.33539968
15 Xiang M, Chang DT, Pollom EL. Second cancer risk after primary cancer treatment with three-dimensional conformal, intensity-modulated, or proton beam radiation therapy. Cancer. 2020;126(15):3560–3568.32426866
16 Yu JB, Soulos PR, Herrin J, . Proton Versus Intensity-Modulated Radiotherapy for Prostate Cancer: Patterns of Care and EarlyToxicity. JNCI : Journal of the National Cancer Institute. 2013;105(1):25–32.23243199
17 Arimura T, Yoshiura T, Matsukawa K, Kondo N, Kitano I, Ogino T. Proton Beam Therapy Alone for Intermediate- or High-Risk Prostate Cancer: An Institutional Prospective Cohort Study. Cancers. 2018;10(4):10.
18 Bryant C, Smith TL, Henderson RH, . Five-Year Biochemical Results, Toxicity, and Patient-Reported Quality of Life After Delivery of Dose-Escalated Image Guided Proton Therapy for Prostate Cancer. International Journal of Radiation Oncology, Biology, Physics. 2016;95(1):422–434.27084658
19 Bryant C, Mendenhall NP, Henderson RH, . Does Race Influence Health-related Quality of Life and Toxicity Following Proton Therapy for Prostate Cancer? American Journal of Clinical Oncology. 2016;39(3):261–265.24710124
20 Bryant C, Hoppe BS, Henderson RH, . Race Does Not Affect Tumor Control, Adverse Effects, or Quality of Life after Proton Therapy. International Journal of Particle Therapy. 2017;3(4):461–472.31772996
21 Bulman GF, Bhangoo RS, DeWees TA, . Dose-volume histogram parameters and patient-reported EPIC-Bowel domain in prostate cancer proton therapy. Radiation Oncology Journal. 2021;39(2):122–128.34619829
22 Colaco RJ, Hoppe BS, Flampouri S, . Rectal toxicity after proton therapy for prostate cancer: an analysis of outcomes of prospective studies conducted at the university of Florida Proton Therapy Institute. International Journal of Radiation Oncology, Biology, Physics. 2015;91(1):172–181.25442338
23 Deville C, Hwang W-T, Barsky AR, . Initial clinical outcomes for prostate cancer patients undergoing adjuvant or salvage proton therapy after radical prostatectomy. In. Vol 59. Philadelphia, Pennsylvania: Taylor & Francis Ltd; 2020:1235–1239.
24 Goenka A, Newman NB, Fontanilla H, . Patient-reported Quality of Life After Proton Beam Therapy for Prostate Cancer: The Effect of Prostate Size. Clinical Genitourinary Cancer. 2017;15(6):704–710.28412047
25 Grewal AS, Schonewolf C, Min EJ, . Four-Year Outcomes From a Prospective Phase II Clinical Trial of Moderately Hypofractionated Proton Therapy for Localized Prostate Cancer. International Journal of Radiation Oncology, Biology, Physics. 2019;105(4):713–722.31199994
26 Ha B, Cho KH, Lee KH, . Long-term results of a phase II study of hypofractionated proton therapy for prostate cancer: moderate versus extreme hypofractionation. Radiation Oncology. 2019;14(1):4.30630500
27 Hattori Y, Iwata H, Nakajima K, . Changes in sexual function and serum testosterone levels in patients with prostate cancer after image-guided proton therapy. Journal of Radiation Research. 2021;62(3):517–524.33675355
28 Henderson RH, Hoppe BS, Marcus RB, . Urinary functional outcomes and toxicity five years after proton therapy for low- and intermediate-risk prostate cancer: Results of two prospective trials. Acta Oncologica. 2013;52(3):463–469.23477359
29 Henderson RH, Bryant C, Hoppe BS, . Five-year outcomes from a prospective trial of image-guided accelerated hypofractionated proton therapy for prostate cancer. Acta Oncologica. 2017;56(7):963–970.28514929
30 Henderson RH, Bryant CM, Nichols RC, . Five- and seven-year outcomes for image-guided moderately accelerated hypofractionated proton therapy for prostate cancer. Acta Oncologica. 2021:1–10.33412980
31 Ho CK, Bryant CM, Mendenhall NP, . Long-term outcomes following proton therapy for prostate cancer in young men with a focus on sexual health. Acta Oncologica. 2018;57(5):582–588.29359988
32 Holtzman AL, Bryant CM, Mendenhall NP, . Patient-Reported Sexual Survivorship Following High-Dose Image-Guided Proton Therapy for Prostate Cancer. Radiotherapy & Oncology. 2019;134:204–210.31005217
33 Iizumi T, Ishikawa H, Sekino Y, . Acute toxicity and patient-reported symptom score after conventional versus moderately hypofractionated proton therapy for prostate cancer. Journal of Medical Radiation Sciences. 2021;19:19.
34 Iwata H, Ishikawa H, Takagi M, . Long-term outcomes of proton therapy for prostate cancer in Japan: a multi-institutional survey of the Japanese Radiation Oncology Study Group. Cancer Medicine. 2018;7(3):677–689.29441697
35 Johansson S, Isacsson U, Sandin F, Turesson I. High efficacy of hypofractionated proton therapy with 4 fractions of 5Gy as a boost to 50Gy photon therapy for localized prostate cancer. Radiotherapy & Oncology. 2019;141:164–173.31431382
36 Kharod SM, Mercado CE, Morris CG, . Postoperative or Salvage Proton Radiotherapy for Prostate Cancer After Radical Prostatectomy. International Journal of Particle Therapy. 2021;7(4):52–64.33829073
37 Kim Y-J, Cho KH, Pyo HR, . A phase II study of hypofractionated proton therapy for prostate cancer. Acta Oncologica. 2013;52(3):477–485.23398594
38 Kubes J, Vondracek V, Andrlik M, . Extreme hypofractionated proton radiotherapy for prostate cancer using pencil beam scanning: Dosimetry, acute toxicity and preliminary results. Journal of Medical Imaging & Radiation Oncology. 2019;63(6):829–835.31486267
39 Kubes J, Haas A, Vondracek V, . Ultrahypofractionated Proton Radiation Therapy in the Treatment of Low and Intermediate-Risk Prostate Cancer-5-Year Outcomes. International Journal of Radiation Oncology, Biology, Physics. 2021;110(4):1090–1097.33587990
40 Lee DT, Mendenhall NP, Smith TL, . Patient-Reported Quality of Life in Men with Transurethral Resection of the Prostate Undergoing Proton Therapy for Management of Prostate Cancer. International Journal of Particle Therapy. 2016;2(4):518–524.30079368
41 Lee HJ, Jr., Macomber MW, Spraker MB, . Analysis of Gastrointestinal Toxicity in Patients Receiving Proton Beam Therapy for Prostate Cancer: A Single-Institution Experience. Advances in radiation oncology. 2019;4(1):70–78.30706013
42 Makishima H, Ishikawa H, Tanaka K, . A retrospective study of late adverse events in proton beam therapy for prostate cancer. Molecular & Clinical Oncology. 2017;7(4):547–552.29046789
43 Mendenhall N, Hoppe B, Nichols R, . Five-year outcomes from 3 prospective trials of image-guided proton therapy for prostate cancer. Int J Radiat Oncol Biol Phys. 2014;88(3):596–602.24521677
44 Mishra MV, Khairnar R, Bentzen SM, . Proton beam therapy delivered using pencil beam scanning vs. passive scattering/uniform scanning for localized prostate cancer: Comparative toxicity analysis of PCG 001-09. Clinical and Translational Radiation Oncology. 2019;19:80–86.31650043
45 Mishra MV, Khairnar R, Bentzen SM, . Patient reported outcomes following proton pencil beam scanning vs. passive scatter/uniform scanning for localized prostate cancer: Secondary analysis of PCG 001-09. Clinical and Translational Radiation Oncology. 2020;22:50–54.32258443
46 Murakami M, Ishikawa H, Shimizu S, . Optimal Androgen Deprivation Therapy Combined with Proton Beam Therapy for Prostate Cancer: Results from a Multi-Institutional Study of the Japanese Radiation Oncology Study Group. Cancers. 2020;12(6):25.
47 Nakajima K, Iwata H, Ogino H, . Acute toxicity of image-guided hypofractionated proton therapy for localized prostate cancer. International Journal of Clinical Oncology. 2018;23(2):353–360.29098520
48 Negoro H, Iizumi T, Mori Y, . Chronoradiation Therapy for Prostate Cancer: Morning Proton Beam Therapy Ameliorates Worsening Lower Urinary Tract Symptoms. Journal of Clinical Medicine. 2020;9(7):16.
49 Takagi M, Demizu Y, Terashima K, . Long-term outcomes in patients treated with proton therapy for localized prostate cancer. Cancer Medicine. 2017;6(10):2234–2243.28879658
50 Takagi M, Demizu Y, Fujii O, . Proton Therapy for Localized Prostate Cancer: Long-Term Results From a Single-Center Experience. International Journal of Radiation Oncology, Biology, Physics. 2020;109(4):964–974.33186616
51 Vargas CE, Hartsell WF, Dunn M, . Hypofractionated Versus Standard Fractionated Proton-beam Therapy for Low-risk Prostate Cancer: Interim Results of a Randomized Trial PCG GU 002. American Journal of Clinical Oncology. 2018;41(2):115–120.26523442
52 Vargas CE, Schmidt MQ, Niska JR, . Initial toxicity, quality-of-life outcomes, and dosimetric impact in a randomized phase 3 trial of hypofractionated versus standard fractionated proton therapy for low-risk prostate cancer. Advances in radiation oncology. 2018;3(3):322–330.30202801