# REFERENCES

1 Rosner MH, Falk RJ. Understanding Work: Moving beyond the RVU. Clin J Am Soc Nephrol. 2020;15(7):1053–1055. doi:10.2215/CJN.12661019 32094244
2 Brookings Institution. The Medicare Physician Fee Schedule Likely to Service as Foundation for Alternative Payment Models. USC-Brookings Schaeffer Inititiative For Health Policy. Published online 2017.
3 McNassor R, Grits D, Said TM, Burkhart RJ, Acuña AJ, Kamath AF. Correlation of Relative Value Units with Surgical Complexity and Physician Workload: A Contemporary Nationwide Analysis of Orthopaedic Procedures. J Am Acad Orthop Surg. 2023;31(8):413–420. doi:10.5435/JAAOS-D-22-00866 36749881
4 Ramirez JL, Gasper WJ, Seib CD, . Patient complexity by surgical specialty does not correlate with work relative value units. Surgery. 2020;168(3):371–378. doi:10.1016/j.surg.2020.03.002 32336468
5 CPT® purpose & mission | American Medical Association. Accessed April 14, 2025. https://www.ama-assn.org/about/cpt-editorial-panel/cpt-purpose-mission
6 RVS Update Committee (RUC) | American Medical Association. Accessed April 10, 2025. https://www.ama-assn.org/about/rvs-update-committee-ruc/rvs-update-committee-ruc
7 Becker ER, Hall K. Physician services in an academic neurology department: Using the resource-based relative-value scale to examine physician activities. J Health Care Financ. 2001;27(4):79–91.
8 Katz S, Melmed G. How Relative Value Units Undervalue the Cognitive Physician Visit: A Focus on Inflammatory Bowel Disease. Gastroenterol Hepatol (N Y). 2016;12(4):240–244.27231455
9 Kumetz EA, Goodson JD. The Undervaluation of Evaluation and Management Professional Services. Chest. 2013;144(3):740–745. doi:10.1378/chest.13-0381 23764970
10 Mathers JAL. The Critical Flaw in Physician Compensation Is Not the Sustainable Growth Rate! Chest. 2015;147(4):e156. doi:10.1378/chest.14-2909
11 Berenson RA, Goodson JD. Finding Value in Unexpected Places — Fixing the Medicare Physician Fee Schedule. N Engl J Med. 2016;374(14):1306–1309. doi:10.1056/NEJMp1600999 26959109
12 Arndt B, Tuan WJ, White J, Schumacher J. Panel workload assessment in US primary care: Accounting for non-face-to-face panel management activities. J Am Board Fam Med. 2014;27(4):530–537. doi:10.3122/jabfm.2014.04.130236 25002007
13 Saag HS, Shah K, Jones SA, Testa PA, Horwitz LI. Pajama Time: Working After Work in the Electronic Health Record. J GEN INTERN MED. 2019;34(9):1695–1696. doi:10.1007/s11606-019-05055-x 31073856
14 Holmgren AJ, Downing NL, Tang M, Sharp C, Longhurst C, Huckman RS. Assessing the impact of the COVID-19 pandemic on clinician ambulatory electronic health record use. Journal of the American Medical Informatics Association. 2022;29(3):453–460. doi:10.1093/jamia/ocab268 34888680
15 Gao J, Moran E, Schwartz A, Ruser C. Case-mix for assessing primary care value (CPCV). Health Serv Manage Res. 2020;33(4):200–206. doi:10.1177/0951484820931063 32552065
16 Department of Veterans Affairs. VHA Directive 1065: Productivity and Staffing Guidance for Specialty Provider Group Practice. 2023.
17 Department of Veterans Affairs. Memorandum: READY-SET-GO Campaign for Updated Productivity Targets. 2025.
18 Department of Veterans Affairs. Meet the OPES Team. Accessed April 10, 2025. https://dvagov.sharepoint.com/sites/VHAOPES/SitePages/Meet-the-team.aspx
19 Tricco AC, Lillie E, Zarin W, . PRISMA Extension for Scoping Reviews (PRISMA-ScR): Checklist and Explanation. Ann Intern Med. 2018;169(7):467–473. doi:10.7326/M18-0850 30178033
20 Butala NM, Hidrue MK, Swersey AJ, . Measuring individual physician clinical productivity in an era of consolidated group practices. Healthcare. 2019;7(4). doi:10.1016/j.hjdsi.2019.02.001
21 Saeed I, Barr K, Palani S, Shafer P, Pizer S. Comparison of Full-Time Equivalent and Clinic Time Labor Input Measures in Productivity Metrics. J Healthc Manage. 2024;69(3):178–189. doi:10.1097/JHM-D-23-00106
22 Tran LD, Wagner TH, Shekelle P, . Assessing and Improving Productivity in Primary Care: Proof of Concept Results for a Novel Value-Based Metric. J Gen Intern Med. 2024;39(12):2317–2323. doi:10.1007/s11606-024-08710-0 38926317
23 Hempel S, Curtis I, Fihn SD, . Primary Care Productivity: Findings from the Literature and Perspectives from a Stakeholder Panel. RAND Corporation. Published online 2021.
24 Apaydin EA, Rose DE, McClean MR, . Association between care coordination tasks with non-VA community care and VA PCP burnout: an analysis of a national, cross-sectional survey. BMC Health Serv Res. 2021;21(1):809. doi:10.1186/s12913-021-06769-7 34384398
25 Goodson JD. Unintended Consequences of Resource-Based Relative Value Scale Reimbursement. JAMA. 2007;298(19):2308. doi:10.1001/jama.298.19.2308 18029836
26 Goodson JD, Shahbazi S, Song Z. Physician Payment Disparities and Access to Services—a Look Across Specialties. J GEN INTERN MED. 2019;34(11):2649–2651. doi:10.1007/s11606-019-05133-0 31385213