# DISCUSSION

The purpose of this scoping review was to describe the size, range, and characteristics of available evidence on measures of specialty medicine physician productivity. We found that the existing literature base on this topic is small with a limited range. Studies included cardiology clinics but lack data from other medicine specialties.

The 3 observational studies we identified all aimed to improve upon wRVU-based productivity measures but differed in their approach. Two studies^20,21^ of cardiology clinics evaluated ways to modify measures for work input (the denominator in the “output/input = productivity” equation) while continuing to use a volume-based measure (patient visits) for work output. One study adjusted their work input measure to account for shared practice resources, while the other used an alternative measure for clinical time instead of FTE. Both studies found that modifying their measures for work input resulted in a more accurate and fair calculation for individual physician productivity.

The most robust new model of physician productivity reconceptualized what information should be used to calculate both work outputs and work inputs.^22^ Strengths of this model, which was based on VHA data and informed by an evidence review and stakeholder panel input,^23^ are that it incorporates patient-important outcomes such as quality, access, and experience and removes volume-based measures from the productivity equation. In this way, the model offers a distinctly different method to measure productivity that would seem to be a better fit with the overall VHA approach to care, which prioritizes patient-centeredness, quality, access, and cost containment. While designed for primary care clinics, this model could be modified for specialty medicine clinics and other types of outpatient practice settings.

The varied aims and approaches of the 3 studies included in this review illustrate how productivity measures can serve multiple different purposes depending on why they are being used and the problem they are trying to solve. For example, Butala et al^20^ used their analysis of productivity adjusted for shared resources to create standard expectations for nurse practitioner to physician ratios and use of clinic rooms. Saeed et al^21^ found that their revised definition of clinical time was a better predictor of wait times than measures based on FTE and could be used to evaluate clinic access. Tran et al^22^ suggested that their productivity model would better account for the interprofessional teamwork hours that generate clinic outputs, and therefore fit better with the primary care “value proposition” than wRVU or volume-based metrics. As VHA continues to evolve its productivity standards, decision-makers may consider using the example of these studies to directly link efforts to increase physician productivity to the specific VHA problem trying to be solved.

## LIMITATIONS

Available evidence regarding specialty medicine physician productivity measures has several limitations. First, the overall size of the literature base is small and of limited range. Data from cardiology practices are included, but other medicine subspecialties are not. While study findings may be applicable to general outpatient practice, some medicine subspecialty practice settings may have unique factors to consider when designing appropriate measures for their work output and input. Second, despite widespread concern that wRVU-based productivity metrics do not capture clinical work outside of patient encounters and therefore do not capture the scope of physician work output, no study directly proposed a measure or model to overcome this problem. Researchers with OPES have used VHA primary care data to develop proxy measures for unobserved workload and create a primary care case-mix algorithm,^15^ but the issue of underestimating actual workload in current VHA productivity calculations remains. Third, while we expected to find relevant studies conducted in non-US settings with applicability to VHA such as the United Kingdom, we did not. Given the small number of US studies that we identified, it is possible that no relevant studies have been conducted in countries with comparable integrated health care systems. If so, this finding highlights another evidence gap.

Limitations of this review include the subjective nature by which we operationalized definitions for productivity and other relevant terms such as efficiency. These terms lack standard definitions and are sometimes used interchangeably. We opted to include studies based on whether their aim to was to update some aspect of the “output/input = productivity” equation. We made this decision so that study findings could be compared to the VHA’s current productivity definition, which is a version of the “output/input = productivity” equation. Other reviewers may have used a different approach, which could have resulted in different decisions regarding eligible studies.

## FUTURE RESEARCH

VHA is unique among US health care systems in terms of its mission, funding, and accountability to Congress and American taxpayers. An argument could be made that VHA’s unique status requires a unique approach to evaluating physician productivity, as well as the other metrics driving health care management decisions. Certain aspects of VHA care make overreliance on wRVU-based metrics particularly problematic. For example, increasing use of community care (health care paid for by VHA but delivered by non-VHA providers in the community) has required VHA physicians to spend more time on care coordination activities,^24^ but this work usually takes place outside of patient encounters and is therefore not counted as productive according to the VHA’s current definition.

In the short term, a risk of using a flawed measure (wRVUs) to assess physician work output is misjudging staffing needs and not providing VHA facilities with the resources that they need to meet patient demand. In the long term, continued reliance on wRVUs as a foundational aspect of US health care including VHA care presents threats to cost containment, as procedures and other services that generate more wRVUs are typically also more expensive to provide.^25^ Similarly, sustaining a balanced physician workforce will become increasingly more difficult as fewer physicians will elect to enter specialties that are undervalued and lower paid yet still essential for patient care.^26^

As a learning health care system that is not dependent on wRVUs for payment, VHA is ideally positioned to develop and test innovative models to measure physician productivity that are aligned with the goal of delivering high-value patient-centered care. Although few in number, existing studies have demonstrated that productivity measures can be reimagined. Moreover, 2 of the 3 studies we identified were conducted within VHA, suggesting that VHA already has the data and expertise to advance this field.

Specific ways that VHA could improve upon current measures of physician productivity include:

- Adapting the model developed by Tran et al^22^, which uses a holistic approach to measure clinic-level productivity, to evaluate specialty clinic settings. Using this kind of model to measure productivity would be more consistent with VHA’s approach to care than a simple work output/input equation and could be used to improve clinic efficiency (how well clinics maximize outputs based on available inputs in terms of time and effort).
- Creating and testing a new measure set for asynchronous clinical work, perhaps one in which various work tasks completed outside of patient encounters are categorized and ranked according to cognitive effort and time requirements, and then applying this new measure set to physician productivity calculations.
- Ensuring that new models or measures developed for physician and clinic-level productivity calculations are based on available, accessible, and timely data and are therefore feasible to implement in practice.

## CONCLUSIONS

We found that available evidence on specialty medicine physician productivity measures is limited. Two observational studies proposed modifications to work input measures but still used volume-based measures for work output. A third observational study described a promising new model developed using VHA primary care data that ties clinic-level productivity to patient outcomes. Important evidence gaps exist, including how to measure clinical work that is completed outside of patient encounters. As a learning health care system, VHA is uniquely positioned to implement and study alternatives to volume-based productivity metrics that align with the value-based outcomes that are important to patients, physicians, and society at large.