# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

Literature flow diagram summarizing results of study selection process.

## OVERVIEW OF INCLUDED STUDIES

Our search identified 174 potentially relevant articles after deduplication and title and abstract screening. Of these, 3 observational studies^20–22^ met eligibility criteria. All 3 were conducted in the US and 2 were conducted in VHA settings. Two studies evaluated productivity measures for specialty physicians and 1 developed a productivity model for primary care. Study characteristics are presented in Table 1.

Table 1 Characteristics of Included Studies

Study | N | Setting | Study Aim | Data Source | Statistical Method(s)
Butala 2019 | 56 cardiologists | Cardiology practice at an academic medical center | Develop a method to measure individual physician outpatient clinical productivity accounting for shared practice resources | Administrative scheduling and hospital data and conversations with practice staff | Compared sequential mixed effects models to GEE and DEA models
Saeed 2024 | 654 providers in 32 clinics | VHA cardiology and orthopedics clinics | Propose a new work input measure (“clinical time”) to replace FTE in productivity calculations | VA Corporate Data Warehouse | Used OLS regression models to validate measures using wait time as an outcome
Tran 2024 | 703 clinics | VHA community-based outpatient (primary care) clinics | Develop and test a multi-dimensional measure of primary care clinic productivity | Healthcare Effectiveness Data and Information Set, VHA Survey of Healthcare Experience of Patients, and VA Corporate Data Warehouse | Used DEA to calculate efficiency scores measuring the degree to which clinics maximized primary care outputs given available FTE

Abbreviations. DEA=data envelopment analysis; FTE=full time equivalency; GEE=generalized estimating equations; OLS=ordinary least squares; VHA=Veterans Health Administration.

Two studies^20,21^ of specialty clinics evaluated methods to calculate individual physician productivity by adjusting the measure for work inputs (the denominator in the “output/input = productivity” equation), and 1 study^22^ of primary care clinics introduced a new model to evaluate clinic-level productivity with novel measures for both work outputs and inputs.

One of the specialty clinic studies, an observational study^20^ based on 2015-2016 data from 56 cardiologists at an academic medical center, used a mixed-effects model to calculate individual physician productivity after adjusting for the effect of shared practice resources (such as exam rooms) and team-based care (nurse practitioner, fellow, and secretarial FTEs). Rather than wRVUs, the study used completed patient visits per half-day per week as the work output measure (the numerator in the “output/input = productivity” equation). By sequentially evaluating 3 mixed-effects models, authors found that adjusting for shared practice resources reduced variation among individual physicians by more than half, representing a way to evaluate productivity more fairly.

A second specialty clinic study^21^ used 2018–2020 data from 32 VHA cardiology and orthopedics clinics representing 654 providers to compare productivity calculations using FTE as the measure of work input to a new measure called “clinical time,” defined as “the amount of time between the start of the first appointment of the day and the estimated end time of the last appointment of the day for each provider.” This value in minutes was then divided by 8 hours to calculate clinical time in days, or “effective clinical time.” The authors’ reasoning for devising this new “clinical time” measure was based on the observation that FTE information is typically self-reported and lacks a consensus definition. While some health systems or clinics may define clinical FTE as a proportion of a 40-hour work week, others may use a different standard or incorporate nonbillable clinical time. Moreover, self-reported FTE information is typically updated infrequently, while “clinic time” can be updated closer to real time using administrative data. The study used patient visits per “effective clinic day” as the work output measure and found that this measure provided a more accurate prediction of clinic access than patients per day per FTE.

A third observational study based on FY19 VHA data from 703 community-based outpatient (primary care) clinics developed a novel metric with the aim of linking investments in team-based primary care to multiple value-based primary care products. In this model, productivity inputs consisted of interprofessional clinical time calculated according to the sum of FTE for all members of the patient care team. Productivity outputs consisted of: 1) clinical quality based data from the Healthcare Effectiveness Data and Information Set; 2) access using a validated composite measure using VA’s Survey of Healthcare Experience of Patients (SHEP); 3) patient experience based on SHEP data; and 4) number of patients served by each clinic based on VHA administrative data adjusted for patients aged 70 or older and the percent expected to have higher-than-average costs. Inputs and outputs were used to calculate a technical efficiency score reflecting the degree to which clinics maximized outputs given their available inputs. Authors propose that these efficiency scores could be used to meaningfully guide productivity improvements that align with value (not volume)-based outcomes important to patients and physicians.

An overview of how these 3 observational studies defined measures of work input and output compared to VHA’s current productivity definition is presented in Figure 1.

Figure 1 Productivity Definitions in VHA and Included Studies

Notes. ^a^ Defined as “clinical time” in days; ^b^ Defined as “the amount of time between the start of the first appointment of the day and the estimated end time of the last appointment of the day for each provider.”

Figure with different definitions of productivity displayed as equations. The first two definitions are a general productivity definition of outputs divided by inputs equals productivity and the current VHA productivity definition of total work relative value units divided by total clinical full-time equivalency equals specialty group practice productivity. The specific productivity definitions from each of the three included studies are displayed in a similar format below the first two definitions.