# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42024622073 (https://www.crd.york.ac.uk/PROSPERO/view/CRD42024622073)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key question was the focus of this review:

- Key Question 1 (KQ1): What measures and models have been evaluated to assess medical specialty physician productivity in ambulatory settings (including time and effort spent in indirect clinical activities such as population health management and care coordination)?

Study eligibility criteria are shown in the table below.

Domain | Eligibility Criteria
Population | Physicians, prioritizing medicine specialty physicians but including studies of primary care physicians if studies otherwise meet eligibility criteria
Intervention | Physician clinical productivity measures or models implemented or tested with real-world data
Comparator | Any
Outcomes | Productivity outcomes, health care quality outcomes, patient-reported outcomes, cost, care coordination outcomes, or unintended consequences
Setting | Ambulatory care, including care delivered via telehealth
Study Design | Any, but may prioritize studies to fit timeline based on a best-evidence approach

For the purposes of this report, we used the following definitions for key terms based our reading of background literature.

Term | Definition Used in this Report
Productivity | Work output divided by time and/or other resources to complete that work
Workload | Total quantity and/or type of work tasks that must be completed in a given timeframe
Efficiency | Work output divided by the cost (ie, time or effort) of completing that work
Value | Quality divided by cost (ie, time or effort)

## SEARCHING AND SCREENING

To identify articles relevant to the key question, a research librarian searched MEDLINE (Ovid), Cochrane, and Scopus databases from inception through December 2024 using terms for productivity and workload (see Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. English-language titles, abstracts, and full-text articles were independently screened by 2 reviewers, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND SYNTHESIS

One reviewer abstracted population, intervention, comparator characteristics, and outcome information from all included studies. Data were checked by another reviewer and disagreements were resolved by consensus. We present themes across the available evidence but did not formally assess risk of bias of individual studies or assess the strength of the body of evidence for a given outcome. This approach is consistent with scoping review methods.^19^