# BACKGROUND

Productivity is a term used in the health care context to refer to the work output from physicians and other clinical staff relative to the time and other resources available to complete that work. How to measure physician productivity accurately and fairly has been a perennial topic of debate. In the current era, most US health systems use work relative value units (wRVUs) as a surrogate measure to approximate physician work output given the lack of another standard measure. Representing 1 component of the 3-component resource-based relative value scale (RBRVS), which also accounts for practice expenses and malpractice insurance costs, wRVUs assign a numerical value to physician work output according to current procedural terminology (CPT) codes applied to a patient visit or procedure.^1^ Although wRVUs were first used in 1992 by the Health Care Financing Administration (now the Centers for Medicare & Medicaid Services [CMS]) for the purposes of standardizing a Medicare fee schedule, the wRVU system of valuing clinical services has been widely adopted by state Medicaid programs and commercial payers.^2^ Therefore, across the range of clinical services provided in the US, most are coded according to CPT and assigned value via wRVUs, making wRVUs a readily available source of information to estimate physician work output. Many health care systems use metrics based on wRVUs, such as total annual wRVUs, to set physician productivity standards (or benchmarks), design physician payment and incentive plans, and allocate resources across clinical services. Use of electronic health records (EHRs) also facilitates use of wRVU data, given that CPT codes are typically part of clinical encounter documentation.

However, despite the widespread use of wRVU-based metrics in health care management decisions, physicians across multiple specialties have expressed concerns about how clinical services are valued in the RBRVS system, the implications of valuing (and therefore charging higher prices for) certain services more than others, and the downstream implications of using wRVUs as a stand-alone measure to assess physician work output.^3,4^

The American Medical Association (AMA) maintains CPT codes, which became the national coding standard for physician and other health care professional services and procedures under the Health Insurance Portability and Accountability Act (HIPAA) in 2020.^5^ The AMA also makes annual recommendations to CMS on fee schedule changes based on input from a Relative Value Scale Update Committee (RUC) that meets throughout the year but conducts its deliberations privately (ie, outside of public view).^6^ According to the AMA, CMS typically accepts more than 90% of the RUC’s recommendations.^6^ A long-standing critique of this arrangement, by which CMS seems to have largely outsourced decision-making regarding Medicare fee schedules to the AMA, is that higher-cost, resource-intensive clinical services, such as procedures, are preferentially valued over evaluation and management services, the so-called “cognitive services” in which the resource being used is the physician’s time and clinical judgement.^1,7–9^ In addition to primary care, internal medicine subspecialties with an outpatient focus including rheumatology, endocrinology, infectious diseases, and pulmonary care are impacted by this chronic undervaluation.^9^

The initial framework of the RBRVS was designed to be applied to procedural services; cognitive services were incorporated later in the process.^10^ Part of this legacy is that a small number of CPT codes exist for evaluation and management services compared to an expansive list of CPT codes for procedural-based services. Physicians providing evaluation and management services have limited choice of CPT codes to assign to an increasingly broad spectrum of outpatient service complexity, which disadvantages physicians in cognitive specialties and contributes to the undervaluation of their clinical services. While many procedures and diagnostic tests have become more efficient and less time intensive over time due to technology improvements, outpatient medicine has become more complex and more time intensive as the population ages and has a higher burden of chronic diseases.^11^ Yet CPT codes and associated wRVUs have not evolved along with these trends. Moreover, CPT codes do not capture work that is completed outside of a patient encounter, such as reviewing records, refilling medications, communicating lab and imaging results, responding to patient messages, coordinating care across services, and managing population health.^12^ The time required to complete these non-billable “asynchronous” clinical work activities has been trending up over time and sharply increased with the onset of the COVID-19 pandemic and a shift away from face-to-face patient care.^13,14^ These asynchronous clinical work activities are a core component of outpatient medical care but are often “not observable or not observed” and therefore not captured in wRVU-based metrics, even though these activities improve care quality and reduce costs.^15^

Although VHA operates as a capitated health care system based on the distribution of Congressionally appropriated funds across Veterans Integrated Service Networks (VISNs) and therefore does not depend on wRVUs as a primary means of payment (although it does bill third-party payers for some health care services), wRVUs are still used by VHA decision-makers as a surrogate measure for physician work output. According to VHA Directive 1065,^16^ specialty group practice productivity is defined as clinical work completed (the group’s total wRVUs) divided by the time available to do that work (the group’s total clinical time, full-time equivalent [FTE]). The range of acceptable productivity falls within the interquartile range (25^th^ to 75^th^ percentile) of the comparator. In past years, specialty group practice productivity has been compared to historical VHA performance, but as of fiscal year 2026 (FY26) the VHA will be primarily using Medical Group Management Association (MGMA) academic median benchmarks to determine productivity standards.^17^ The Office of Productivity, Efficiency & Staffing (OPES) “assists VHA leadership in developing effective management tools, systems, and studies to optimize clinical productivity and efficiency so that informed staffing decisions are made.”^18^ Underperforming groups identified with OPES management tools may be referred to the VISN Director for review and development of performance improvement plans.

Although VHA’s reasons for using wRVU-based metrics primarily relate to staffing rather than billing, the same concerns about using wRVUs as a surrogate for physician work output in non-VA health care settings apply to the VHA context. The purpose of this report is to review the available evidence on physician productivity measures to identify potential alternatives to wRVU-based metrics. This report was requested by the Specialty Care Services and Chiefs of Medicine Field Advisory Board and therefore focuses on medical specialty physicians delivering care in the outpatient setting. Given an interest in understanding the size, range, and characteristics of available evidence, we opted to conduct a scoping review, which is a type of systematic review that identifies main themes across a body of literature.^19^ The findings of this report may inform VHA activities related to measuring physician productivity.