# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson, MLIS for literature searching, screening, and data abstraction efforts, Payten Sonnen for screening and data abstraction efforts and editorial and citation management support, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Paul R. Conlin, MD
  Chief, Medical Service
  VA Boston Healthcare System
- Ajay Dhawan, MD
  Chief Officer
  VHA Specialty Care Services