# ABBREVIATIONS TABLE

Abbreviation: Definition
AMA: American Medical Association
CMS: Centers for Medicare and Medicaid Services
CPT: Current procedural terminology
DEA: Data envelopment analysis
FTE: Full-time equivalent
GEE: Generalized estimating equivalents
MGMA: Medical Group Management Association
OLS: Ordinary least squares
OPES: Office of Productivity, Efficiency, and Staffing
RUC: Relative Value Scale Update Committee
SHEP: Survey of Healthcare Experience of Patients
VA: Veterans Affairs
VHA: Veterans Health Administration
VISN: Veterans Integrated Service Network
RVU: Relative value unit
RBRVS: Resource-based relative value scale
wRVU: Work relative value unit