# REFERENCES

1 Chacko A, Jensen SA, Lowry LS, . Engagement in Behavioral Parent Training: Review of the Literature and Implications for Practice. Clin Child Fam Psychol Rev. 2016;19(3):204–15.27311693
2 Centers for Disease Control and Prevention. Parent training Programs: insight for Practitioners. Atlanta, GA: CDC; 2009.
3 Forehand RL, McMahon RJ. Helping the noncompliant child: A clinician’s guide to parent training. New York: Guilford. 1981.
4 Barkley RA. Defiant children: A clinician’s manual for assessment and parent training. (3rd ed. ed.). New York: Guilford. 2013.
5 Kaminski JW, Valle LA, Filene JH, . A meta-analytic review of components associated with parent training program effectiveness. J Abnorm Child Psychol. 2008;36(4):567–89.18205039
6 Smith BH, Barkley RA, Shapiro CJ. Attention deficit hyperactivity disorder. In M. E. J. & R. A. Barkley (Eds.), Treatment of Childhood Disorders (3rd ed. ed., pp. 65–136). New York: Guilford. 2006.
7 Hohlfeld ASJ, Harty M, Engel ME. Parents of children with disabilities: A systematic review of parenting interventions and self-efficacy. Afr J Disabil. 2018;7:437.30473997
8 Savage L, Tarabulsy GM, Pearson J, . Maternal history of childhood maltreatment and later parenting behavior: A meta-analysis. Dev Psychopathol. 2019;31(1):9–21.30757988
9 Chamberlain C, Gee G, Harfield S, . Parenting after a history of childhood maltreatment: A scoping review and map of evidence in the perinatal period. PLoS ONE. 2019;14(3).
10 Backhaus S, Leijten P, Jochim J, . Effects over time of parenting interventions to reduce physical and emotional violence against children: a systematic review and meta-analysis. EClinicalMedicine. 2023;60:102003.37251634
11 Appleyard K, Berlin LJ, Rosanbalm KD, . Preventing early child maltreatment: implications from a longitudinal study of maternal abuse history, substance use problems, and offspring victimization. Prev Sci. 2011;12(2):139–49.21240556
12 Engur B. Parents with Psychosis: Impact on Parenting and Parent-Child Relationship. J Child Adolesc Behav. 5: 327. doi: 10.4172/2375-4494.1000327. 2017.
13 Galovski TE, Street AE, Creech S, . State of the Knowledge of VA Military Sexual Trauma Research. J Gen Intern Med. 2022;37(Suppl 3):825–832.36042078
14 Creech SK, Hadley W, Borsari B. The Impact of Military Deployment and Reintegration on Children and Parenting: A Systematic Review. Prof Psychol Res Pr. 2014;45(6):452–464.25844014
15 Zvara BJ, Mills-Koonce WR, Appleyard Carmody K, . Childhood sexual trauma and subsequent parenting beliefs and behaviors. Child Abuse Negl. 2015;44:87–97.25680655
16 Creech SK, Misca G. Parenting with PTSD: A Review of Research on the Influence of PTSD on Parent-Child Functioning in Military and Veteran Families. Front Psychol. 2017;8:1101.28713306
17 Christie H, Hamilton-Giachritsis C, Alves-Costa F, . The impact of parental posttraumatic stress disorder on parenting: a systematic review. Eur J Psychotraumatol. 2019;10(1):1550345.30693071
18 Goodman SH, Simon H, McCarthy L, . Testing Models of Associations Between Depression and Parenting Self-efficacy in Mothers: A Meta-analytic Review. Clin Child Fam Psychol Rev. 2022;25(3):471–499.35556193
19 Kritikos TK, Comer JS, He M, . Combat Experience and Posttraumatic Stress Symptoms among Military-Serving Parents: a Meta-Analytic Examination of Associated Offspring and Family Outcomes. J Abnorm Child Psychol. 2019;47(1):131–148.29687429
20 Creech SK, Swift R, Zlotnick C, . Combat exposure, mental health, and relationship functioning among women veterans of the Afghanistan and Iraq wars. J Fam Psychol. 2016;30(1):43–51.26348108
21 Hoerster KD, Lehavot K, Simpson T, . Health and health behavior differences: U.S. Military, veteran, and civilian men. Am J Prev Med. 2012;43(5):483–9.23079170
22 Bagalman E. Mental Disorders Among OEF/OIF Veterans Using VA Health Care: Facts and Figures. Congressional Research Service; 2013.
23 Wadsworth SM, MacDermid S, Riggs DS, . Risk and resilience in U.S. military families. 1st 2011. ed New York, NY: Springer New York; 2011.
24 Davis L, Hanson SK, Zamir O, . Associations of contextual risk and protective factors with fathers’ parenting practices in the postdeployment environment. Psychological Services. 2015;12(3):250–60.26213794
25 Yehuda R, Lehrner A. Intergenerational transmission of trauma effects: putative role of epigenetic mechanisms. World Psychiatry. 2018;17(3):243–257.30192087
26 Leijten P, Scott S, Landau S, . Individual Participant Data Meta-analysis: Impact of Conduct Problem Severity, Comorbid Attention-Deficit/Hyperactivity Disorder and Emotional Problems, and Maternal Depression on Parenting Program Effects. J Am Acad Child Adolesc Psychiatry. 2020;59(8):933–943.32084529
27 McGowan J, Sampson M, Salzwedel DM, . PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–6.27005575
28 metafor: Meta-analysis package for R. version 3.8-1. The Comprehensive R Archive Network: https://cran.r-project.org/web/packages/metafor/index.html; 2023.
29 Wolfenden L, Calam R, Drake RJ, . The Triple P Positive Parenting Program for Parents With Psychosis: A Case Series With Qualitative Evaluation. Front Psychiatry. 2022;13:791294.35273529
30 Serravalle L, Iacono V, Wilson AL, . Improved Parent-Child Interactions Predict Reduced Internalizing Symptoms Among the Offspring of Parents with Bipolar Disorder Undergoing a Prevention Program: A Proof-of-Concept Study. Research on Child and Adolescent Psychopathology. 2021;49(6):817–830.33544277
31 Jones SH, Jovanoska J, Calam R, . Web-based integrated bipolar parenting intervention for parents with bipolar disorder: a randomised controlled pilot trial. Journal of Child Psychology & Psychiatry & Allied Disciplines. 2017;58(9):1033–1041.28512921
32 Kaplan K, Solomon P, Salzer MS, . Assessing an Internet-based parenting intervention for mothers with a serious mental illness: a randomized controlled trial. Psychiatric Rehabilitation Journal. 2014;37(3):222–31.24978623
33 van der Zanden RA, Speetjens PA, Arntz KS, . Online group course for parents with mental illness: development and pilot study. Journal of Medical Internet Research. 2010;12(5):e50.21169178
34 Compas BE, Forehand R, Keller G, . Randomized controlled trial of a family cognitive-behavioral preventive intervention for children of depressed parents. Journal of Consulting & Clinical Psychology. 2009;77(6):1007–20.19968378
35 Sanford M, Byrne C, Williams S, . A pilot study of a parent-education group for families affected by depression. Canadian Journal of Psychiatry - Revue Canadienne de Psychiatrie. 2003;48(2):78–86.12655904
36 Fernando SC, Griepenstroh J, Bauer U, . Primary prevention of mental health risks in children of depressed patients: Preliminary results from the Kanu-intervention. Mental Health and Prevention. 2018;11:33–40.
37 Jones S, Calam R, Sanders M, . “A pilot web based positive parenting intervention to help bipolar parents to improve perceived parenting skills and child outcomes”: Addendum. Behavioural and Cognitive Psychotherapy. 2015;43(2):256.
38 Serravalle L, Iacono V, Wilson AL, . Correction to: Improved Parent-Child Interactions Predict Reduced Internalizing Symptoms Among the Offspring of Parents with Bipolar Disorder Undergoing a Prevention Program: A Proof-of-Concept Study. Res Child Adolesc Psychopathol. 2021;49(6):833.33835373
39 Sanders MR. Development, Evaluation, and Multinational Dissemination of the Triple P-Positive Parenting Program. Annual Review of Clinical Psychology. 2012;8(1):345–379.
40 Sanders MR, Kirby JN, Tellegen CL, . The Triple P-Positive Parenting Program: A systematic review and meta-analysis of a multi-level system of parenting support. Clinical Psychology Review. 2014;34(4):337–357.24842549
41 Dinkmeyer D, McKay GD. The parent’s handbook: systematic training for effective parenting Circle Pines: American Guidance Service; 1989.
42 O’Shea A, Kaplan K, Solomon P, . Randomized Controlled Trial of an Internet-Based Educational Intervention for Mothers With Mental Illnesses: An 18-Month Follow-Up. Psychiatric Services. 2019;70(8):732–735.31023190
43 Mogil C, Hajal N, Aralis H, . A Trauma-Informed, Family-Centered, Virtual Home Visiting Program for Young Children: One-Year Outcomes. Child Psychiatry & Human Development. 2021;07:07.
44 Julian MM, Muzik M, Kees M, . Intervention effects on reflectivity explain change in positive parenting in military families with young children. Journal of Family Psychology. 2018;32(6):804–815.29878806
45 Lester P, Liang LJ, Milburn N, . Evaluation of a Family-Centered Preventive Intervention for Military Families: Parent and Child Longitudinal Outcomes. J Am Acad Child Adolesc Psychiatry. 2016;55(1):14–24.26703905
46 James Riegler L, Raj SP, Moscato EL, . Pilot trial of a telepsychotherapy parenting skills intervention for veteran families: Implications for managing parenting stress during COVID-19. Journal of Psychotherapy Integration. 2020;30(2):290–303.
47 Gewirtz AH, DeGarmo DS, Zamir O. “After deployment, adaptive parenting tools: 1-year outcomes of an evidence-based parenting program for military families following deployment”: Correction. Prevention Science. 2018;19(4):600–601.29094231
48 Forgatch MS, Patterson GR. Parent management training—Oregon model: An intervention for antisocial behavior in children. In: Weisz JR, Kazdin AE, eds. Evidence-based psychotherapies for children and adolescents. New York, NY: Guilford; 2010.
49 Lester P, Saltzman WR, Woodward K, . Evaluation of a family-centered prevention intervention for military children and families facing wartime deployments. Am J Public Health. 2012;102 Suppl 1(Suppl 1):S48–54.22033756
50 Beardslee W, Lester P, Klosinski L, . Family-centered preventive intervention for military families: implications for implementation science. Prev Sci. 2011;12(4):339–48.21761154
51 Gewirtz AH, DeGarmo DS, Zamir O. Effects of a Military Parenting Program on Parental Distress and Suicidal Ideation: After Deployment Adaptive Parenting Tools. Suicide & Life-Threatening Behavior. 2016;46 Suppl 1:S23–31.27094107
52 Muzik M, Rosenblum KL, Alfafara EA, . Mom Power: preliminary outcomes of a group intervention to improve mental health and parenting among high-risk mothers. Archives of Women’s Mental Health. 2015;18(3):507–21.
53 Gewirtz AH, DeGarmo DS, Zamir O. After Deployment, Adaptive Parenting Tools: 1-Year Outcomes of an Evidence-Based Parenting Program for Military Families Following Deployment. Prev Sci. 2018;19(4):589–599.28913717
54 Gewirtz AH, Pinna KL, Hanson SK, . Promoting parenting to support reintegrating military families: after deployment, adaptive parenting tools. Psychological Services. 2014;11(1):31–40.24564441
55 Severe S. How to behave so your children will too! : practical strategies to make discipline simple and your life easier London: Vermilion; 2000.
56 Jones S, Wainwright LD, Jovanoska J, . An exploratory randomised controlled trial of a web-based integrated bipolar parenting intervention (IBPI) for bipolar parents of young children (aged 3-10). BMC Psychiatry. 2015;15:122.26047808
57 Pinna KL, Hanson S, Zhang N, . Fostering resilience in National Guard and Reserve families: A contextual adaptation of an evidence-based parenting program. American Journal of Orthopsychiatry. 2017;87(2):185–193.28206806
58 Butler J, Gregg L, Calam R, . Parents’ Perceptions and Experiences of Parenting Programmes: A Systematic Review and Metasynthesis of the Qualitative Literature. Clin Child Fam Psychol Rev. 2020;23(2):176–204.31820298
59 Farnsworth JK, Drescher KD, Nieuwsma JA, . The Role of Moral Emotions in Military Trauma: Implications for the Study and Treatment of Moral Injury. Review of General Psychology. 2014;18(4):249–262.
60 Purcell N, Koenig CJ, Bosch J, . Veterans’ Perspectives on the Psychosocial Impact of Killing in War. The Counseling Psychologist. 2016;44(7):1062–1099.
61 Hao Y, Franco JH, Sundarrajan M, . A Pilot Study Comparing Tele-therapy and In-Person Therapy: Perspectives from Parent-Mediated Intervention for Children with Autism Spectrum Disorders. J Autism Dev Disord. 2021;51(1):129–143.32377905
62 Comer JS, Furr JM, Miguel EM, . Remotely delivering real-time parent training to the home: An initial randomized trial of Internet-delivered parent-child interaction therapy (I-PCIT). J Consult Clin Psychol. 2017;85(9):909–917.28650194
63 Daley D, Van Der Oord S, Ferrin M, . Practitioner Review: Current best practice in the use of parent training and other behavioural interventions in the treatment of children and adolescents with attention deficit hyperactivity disorder. Journal of Child Psychology & Psychiatry & Allied Disciplines. 2018;59(9):932–947.29083042
64 Doyle FL, Morawska A, Higgins DJ, . Policies are Needed to Increase the Reach and Impact of Evidence-Based Parenting Supports: A Call for a Population-Based Approach to Supporting Parents, Children, and Families. Child Psychiatry Hum Dev. 2023;54(3):891–904.34989941
65 Day JJ, Sanders MR. Do Parents Benefit From Help When Completing a Self-Guided Parenting Program Online? A Randomized Controlled Trial Comparing Triple P Online With and Without Telephone Support. Behav Ther. 2018;49(6):1020–1038.30316482
66 Waldrop J, Baker M, Salomon R, . Parenting Interventions and Secondary Outcomes Related to Maternal Mental Health: A Systematic Review. Maternal & Child Health Journal. 2021;25(6):870–880.33905064
67 Branco MSS, Altafim ERP, Linhares MBM. Universal Intervention to Strengthen Parenting and Prevent Child Maltreatment: Updated Systematic Review. Trauma Violence Abuse. 2022;23(5):1658–1676.33973499
68 Altafim ERP, Linhares MBM. Universal violence and child maltreatment prevention programs for parents: A systematic review. Psychosocial Intervention. 2016;25(1):27–38.
69 Altafim ERP, Pedro MEA, Linhares MBM. Effectiveness of ACT Raising Safe Kids Parenting Program in a developing country. Children and Youth Services Review. 2016;70:315–323.
70 Radley J, Grant C, Barlow J, . Parenting interventions for people with schizophrenia or related serious mental illness. Cochrane Database of Systematic Reviews. 2021;10:CD013536.34666417
71 Buric J, Juretic J, Stulhofer A. The role of socialization, dispositional and behavioral variables in the dynamics of sexting among adolescents. Psihologijske Teme. 2018;27(3):409–435.
72 Creech SK, Pearson R, Saenz JJ, . Pilot trial of Strength at Home Parents, a trauma-informed parenting support treatment for veterans. Couple Family Psychol. 2022;11(3):205–216.36185500
73 Taft CT, Creech SK, Gallagher MW, . Strength at Home Couples program to prevent military partner violence: A randomized controlled trial. J Consult Clin Psychol. 2016;84(11):935–945.27599224
74 Sullivan KS, Ancharski K, Wortham W, . Feasibility and Preliminary Impact of a Community-Based Intervention for Maternal PTSD and Parenting: Parenting-STAIR Pilot. J Child Fam Stud. 2023.
75 Watson KH, Dunbar JP, Thigpen J, . Observed parental responsiveness/warmth and children’s coping: cross-sectional and prospective relations in a family depression preventive intervention. Journal of Family Psychology. 2014;28(3):278–86.24773219
76 Breslend NL, Parent J, Forehand R, . Children of parents with a history of depression: The impact of a preventive intervention on youth social problems through reductions in internalizing problems. Development & Psychopathology. 2019;31(1):219–231.29229006
77 Lester P, Saltzman WR, Woodward K, . Evaluation of a family-centered prevention intervention for military children and families facing wartime deployments. American Journal of Public Health. 2012;102 Suppl 1:S48–54.22033756
78 Goldstein MJ. Psychoeducation and relapse prevention. Int Clin Psychopharmacol. 1995;9 Suppl 5:59–69.7622836
79 Kuipers L, Leff J, Lam D. Family work for schizophrenia: a practical guide London: Gaslell; 1992.
80 Cunningham CE, Bremner R, Boyle M. Large group community-based parenting programs for families of preschoolers at risk for disruptive behaviour disorders: utilization, cost effectiveness, and outcome. J Child Psychol Psychiatry. 1995;36(7):1141–59.8847377
81 Shapiro LE, Sprague RK, Ebscohost. The relaxation & stress reduction workbook for kids : help for children to cope with stress, anxiety & transitions Oakland, Calif: New Harbinger Publications; 2009.
82 Kendall PC, Hedtke KA, Child, . Cognitive-behavioral therapy for anxious children : therapist manual. 3rd ed Ardmore, Pa: Workbook Pub; 2006.
83 Abramowitz JS, ProQuest. The stress less workbook : simple strategies to relieve pressure, manage commitments, and minimize conflicts. 1st ed New York, N.Y: Guilford Press; 2012 Guilford self-help workbook series).
84 Patterson GR. Coersive Family Process Eugene, OR: Castalia Press; 1982.
85 Achenbach TM. Developmental psychopathology. 2nd ed New York ; Chichester: Wiley; 1982.
86 Böszörményi-Nagy I. Grondbeginselen van de contextuele benadering (The foundings of the contextual therapy) Haarlem, the Netherlands: De Toorts; 2000.
87 Beardslee WR, Gladstone TR, O’Connor EE. Transmission and prevention of mood disorders among children of affectively ill parents: a review. J Am Acad Child Adolesc Psychiatry. 2011;50(11):1098–109.22023998
88 Wiegand-Grefe S, Cronemeyer B, Plass A, . Comparison of mental abnormalities in children of mentally ill parents from different points of view: Effects of a manualized family intervention. Kindheit und Entwicklung: Zeitschrift fur Klinische Kinderpsychologie. 2013;22(1):31–40.
89 Rotheram-Borus MJ, Lee M, Lin YY, . Six-year intervention outcomes for adolescent children of parents with the human immunodeficiency virus. Arch Pediatr Adolesc Med. 2004;158(8):742–8.15289245
90 Beardslee WR, Wright EJ, Gladstone TR, . Long-term effects from a randomized trial of two public health preventive interventions for parental depression. Journal of Family Psychology. 2007;21(4):703–13.18179342
91 Layne CM, Saltzman WR, Poppleton L, . Effectiveness of a school-based group psychotherapy program for war-exposed adolescents: a randomized controlled trial. J Am Acad Child Adolesc Psychiatry. 2008;47(9):1048–62.18664995
92 Forgatch MS, Kjobli J. Parent Management Training-Oregon Model: Adapting Intervention with Rigorous Research. Family Process. 2016;55(3):500–13.27283222
93 Julian MM, Muzik M, Kees M, . Strong Military Families Intervention Enhances Parenting Reflectivity and Representations in Families with Young Children. Infant Mental Health Journal. 2018;39(1):106–118.29286541
94 Beardslee WR, Klosinski LE, Saltzman W, . Dissemination of family-centered prevention for military and veteran families: adaptations and adoption within community and military systems of care. Clin Child Fam Psychol Rev. 2013;16(4):394–409.24129478
95 Aguilar JM, Cassedy AE, Shultz EL, . A Comparison of 2 Online Parent Skills Training Interventions for Early Childhood Brain Injury: Improvements in Internalizing and Executive Function Behaviors. Journal of Head Trauma Rehabilitation. 2019;34(2):65–76.30499926