# ACKNOWLEDGMENTS

The authors are grateful to Stacy Lavin, PhD, and Liz Wing, MA, for editorial and citation management support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Marsden McGuire, MD, MBA
  Director
  Continuum of Care and General Mental Health, Office of Mental Health and Suicide Prevention, Department of Veterans Affairs

- Shirley Glynn, PhD
  Clinical Research Psychologist
  Department of Veterans Affairs

- Jennifer Strauss, PhD
  National Director, Women and Gender-Related Mental Health
  Office of Mental Health and Suicide Prevention, Department of Veterans Affairs

- Theresa Schmitz, PhD
  National Director, Family Services
  Office of Mental Health and Suicide Prevention, Department of Veterans Affairs

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Suzannah Creech, PhD
  Research Psychologist
  Center of Excellence for Research on Returning War Veterans

- Shelley Fenstermacher, PhD
  Clinical Psychologist
  VA Greater Los Angeles Healthcare System

- Stacey Pollack, PhD
  National Director
  Program Policy Implementation Office of Mental Health and Suicide Prevention

- Michelle Sherman, PhD, LP, ABPP
  Professor
  Department of Family Medicine and Community Health University of Minnesota

- Abigail Gewirtz PhD, MA
  Foundation Professor
  Department of Psychology, Arizona State University

- Johanna Thompson-Hollands, Ph.D.
  Staff Psychologist
  National Center for PTSD (Behavioral Science Division)

- Assistant Professor
  Boston University Chobanian & Avedisian School of Medicine

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix G for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.