# DISCUSSION

We identified 14 unique studies, with most of these (64%; N = 9) being relevant to KQ2 (parent with a history of SMI). Half of the studies were RCTs, with only 1 rated as low ROB. The other studies were a mix of nonrandomized design with 3 being rated as having serious ROB concerns. In total, the studies in this review encompassed 5 major intervention types (ie, multi-family groups, individual family therapy, home visitation with live coaching, chat-based virtual groups, and self-directed programs) with a slim majority (57%) being delivered in person. The majority of included studies took a family-system perspective and involved more than 1 member of the family (eg, spouse/co-parent, child); most (N = 8) directly involve children in the deployment of the behavioral parenting program. Of the 14 included studies, 8 studies reported on the uptake of parenting skills; 71% (N = 6) demonstrated significant improvements in parenting skills and were included in KQ4 on intervention characteristics. Of note, we did not identify any studies that recruited families in which 1 of the parents was a survivor of adult sexual trauma. Moreover, none of the included studies captured sexual trauma histories in the included samples.

To provide context for the findings described in this report, we conducted COE ratings for outcomes prioritized by VA operational partners from the VA Office of Mental Health and Suicide Prevention: parenting skills, self-efficacy in parenting, parental stress, emotion regulation of parent, and family functioning/conflict. These COE ratings reflect the degree of confidence we have in the summary findings. We conducted our COE assessments by intervention type (eg, in-person group) across the KQ1 and KQ2 outcomes and presented findings for randomized and observational studies separately. Overall, we note that while the effect estimates were consistent in showing a benefit of behavioral parenting programs, our confidence assessments were frequently downgraded because of ROB concerns. We also downgraded studies for indirectness if the tested behavioral parenting program did not align with elements VA operational partners indicated would enhance feasibility of VA implementation (eg, direct involvement of child) or if the study was conducted in a population that was less applicable to the Veteran population (eg, only conducted among parents with a SMI less prevalent in the Veteran population).

KQ1 Key Findings and Certainty of Evidence: Parents with a History of Sexual Trauma

We identified no eligible studies.

KQ2 Key Findings and Certainty of Evidence: Parents with a History of Serious Mental Illnesses

In total, we identified 9 eligible studies (N = 904 families) that assessed parenting skills programs among parents with SMI. Most studies had small sample sizes, with 4 having high/serious ROB concerns. The dominant SMI population assessed across these studies was parental history of MDD. Parenting programs used 4 main delivery methods: in-person multi-family groups, in-person home visits with a self-directed workbook, online chat-based groups, and web-based self-directed modules. A slim majority (55%) cited an evidence-based parenting program as the basis for their intervention, and most did not directly involve the child as part of the parenting skills training program. Yet, of the interventions delivered in person, all involved another family member (ie, spouse, child).

The overall trend was towards positive changes in parent, child, and family outcomes; yet not all achieved statistical significance. The lack of significance might be due, in part, to insufficient power due to small sample sizes in most studies.

The majority (69%; 9 of 13 reported outcomes) of parent-centered outcomes assessed across these studies reported significant effects of behavioral parenting programs among families with at least 1 parent with SMI. Even among those that were not significant, studies trended towards improvements. While a smaller percentage of studies reported significant outcomes for the prioritized family- (40%; 2 of 5 studies) and child-centered outcomes (57%; 4 of 7 studies), all studies reported some improvements in these outcomes.

Across nearly all outcomes, COE ranged from low to very low (Table 7). Ratings were commonly downgraded when interventions contained elements VA operational partners indicated would make VA implementation less feasible (ie, home-based, involved children, chat-based only) or were conducted in populations with conditions less prevalent than those found among Veterans with mental health conditions (eg, assessed only among parents with bipolar disorder vs parents with a history of MDD). Also, outcomes were commonly downgraded due to ROB issues. The majority of included RTCs were rated as high ROB, and most of the included studies were observations with ROB challenges. The only outcome to be rated as moderate COE was parental stress assessed in a low ROB RCT of a web-based self-directed program.

Table 7 Certainty of Evidence for Parenting Skills, Parental Self-efficacy, Parental Stress, and Family Functioning Among Parents With a History of Serious Mental Illness

Outcome | Number of Studies | Findings | Certainty of Evidence (Rationale)
Group-based In Person
Parental skills | 1 RCT (25 patients) | Positive parenting: F = 0.3 (p > 0.10),; hostile parenting: F = 0.0 (p > 0.10),; consistency: F =2 .6 (p > 0.10); | Low certainty; (downgraded for serious ROB and serious imprecision)
Parental skills | 1 observational study (66 patients) | Parental negativity: b= −0.17 (SE 0.04) (p > 0.001); Wald Z = 16.08 (p > 0.001); Parental positivity: Wald Z = 22.17 (p < 0.001) | Very low certainty; (downgraded for serious ROB, serious indirectness, and serious imprecision)
Group-based Chat Only
Parenting skills | 1 observational study (28 patients) | Laxness: t = 2.90, d = 0.52, p = 0.007;; Overactivity: t = 4.02, d = 0.48, p = 0.000 | Very low certainty; (downgraded for serious ROB, serious indirectness, and serious imprecision)
Home-based
Parenting skills | 1 observational study (5 patients) | Total parenting: t = 8.9, d = 3.28, p = 0.003 | Very low certainty; (downgraded for serious ROB, serious indirectness, serious imprecision)
Web-based Self-directed
Parenting skills | 3 RCTs (267 patients) | Change in total parenting: Difference in slope ranged from 0.03 (p = 0.24) to 0.94 (p < 0.001) and t-test −1.7 (p = 0.1) d = 0.49 to −1.25 (p = 0.23) d = 0.26 | Very low certainty; (downgraded for serious ROB, serious indirectness, and serious imprecision)
Group-based In Person
Parenting self-efficacy | 1 RCT (25 patients) | Sense of parenting competence: F = 3.7, df 30, (p = 0.06) | Low certainty; (downgraded for serious ROB, serious imprecision)
Group-based Chat Only
Parenting self-efficacy | 1 observational study (28 patients) | Incompetence: t = 3.13, d = 0.61, p = 0.004,; Competence: t = 2.81, d = 0.46, p = 0.009 | Very low certainty; (downgraded for serious ROB, serious indirectness, serious imprecision)
Home-based
Parenting self-efficacy | 1 observational study (5 patients) | Behavior: t = −8.9, d = 4.24, p = 0.003,; setting: t = 9.6, d = 3.19, p = 0.002 | Very low certainty; (downgraded for serious ROB, serious indirectness, and very serious imprecision)
Web-based Self-directed
Parenting self-efficacy | 2 RCTs (228 patients) | Parenting confidence: difference in slope −1.17 (SE 0.41), (95% CI [−1.98, −0.37]) p < 0.01; Parenting sense of competence: t = 0.56, d = 0.19, p = 0.58; HFPI parental efficacy: t = −1.39, d = 0.24, p = 0.17 | Very low certainty; (downgraded for serious ROB, serious inconsistency, serious indirectness, and serious imprecision)
Web-based Self-directed
Parental Stress | 1 RCT (97 patients) | Parenting stress index: Difference in slope: 1.94 (SE 0.77) (95% CI [0.42, 3.45]), p = 0.01 | Moderate certainty; (downgraded for serious indirectness)
In-person Individual + Group
Family conflict and functioning | 1 observational study (71 patients) | Parent-child-relationship inventory for children: pre- and post-test ratings of the parent-child relationship did not significantly differ between both groups on any of the subscales (all p > .04); Care subscale: d = 0.18 (95% CI [−0.32, 0.69]); Control subscale: d = −0.08 (95% CI [−0.58, 0.43]); Limitations subscale: d = −0.48 (95% CI [−1.00, 0.02]); Confidence subscale: d = 0.34 (95% CI [−0.17, 0.85]) | Very low certainty; (downgraded for serious ROB, serious indirectness, and serious imprecision)
In-person Group-based
Family conflict and functioning | 1 RCT (25 patients) | Parental conflict with other parent effect estimate: F = 1.5; Family conflict scale: effect estimate = 0.4; Family assessment device: effect estimate F = 6.6, p < 0.05 | Low certainty; (downgraded for serious ROB, and serious imprecision)
Family conflict and functioning | 1 observational study (66 patients) | Dyadic mutuality: Wald Z = 22.18 (p < 0.001), b = 0.15, SE = 0.04 (p < 0.001) | Very low certainty; (downgraded for serious ROB, serious indirectness, and serious imprecision)
Web-based Self-directed
Family conflict and functioning | 2 RCT (228 patients) | Family coherence: Difference in slope: 0.05 (SE 0.10), p = 0.62 (95% CI [−0.14, 0.23]); Family coping inventory: t = −0.2, d = 0.07, p = 0.84 | Very low certainty(downgraded for serious ROB, serious indirectness, serious imprecision)

KQ3 Key Findings and Certainty of Evidence: Parents with a History of Military Service

In total, we identified 5 studies (N = 3,268 families; N = 4,772 participants) that assessed the impact of parenting skills training interventions among families with a history of military service. Most studies were nonrandomized designs (N = 3) and were conducted among families with at least 1 active-duty parent. Parenting programs used 3 main delivery methods: individual family therapy (2 studies), multi-family groups (2 studies), and virtual home visits with live coaching (1 study). Most studies cited an evidence-based parenting program as the basis for their intervention approach and directly involved the child as part of the parenting skills training program. Spousal involvement was also common in these interventions.

The overall trend was towards improvements in key parent, family, and child outcomes, though not all were significant. Effect sizes were generally modest. We observed no clear pattern across intervention types for key outcomes, but these outcomes were reported infrequently across the included studies. No studies reported on the impacts on parental self-efficacy or parenting knowledge. Yet our confidence assessments were frequently downgraded. Across parent-centered outcomes, the COE ranged from moderate to very low (Table 8). Reasons for downgrading COE were ROB issues and indirectness of the population (eg, National Guard and Reserve soldiers and spouses only). We also downgraded on indirectness for interventions with direct child engagement (ie, virtual home visit model) and those that were conducted in observational studies with considerable ROB issues. For family-focused outcomes, the COE ranged from moderate to very low. Both interventions involved models that directly engaged children and/or were fashioned after a home visit model. Also, there were ROB issues; there was serious ROB in the uncontrolled before-after study.

Table 8 Certainty of Evidence for Parenting Skills, Parental Stress, and Parental Emotion Regulation Among Military-connected Families

Outcome | Number of Studies | Findings | Certainty of Evidence (Rationale)
In-person Group
Parenting skills | 1 RCT (336 patients) | Β = 0.16, p <0.01 Change in baseline to 12-month follow up latent construct of observed parenting | Low certainty; (downgraded for serious ROB, and serious indirectness)
Virtual Individual
Parental stress | 1 RCT (349 patients) | Change in baseline to 12 months = 1.43, d = 0.20, p > 0.05 | Moderate certainty; (downgraded for serious indirectness)
Virtual Home Visitation Live Coaching
Parental stress | 1 observational study (22 patients) | t test=t(19) 4.36, p −0.0003, d = 0.98 | Very low certainty; (downgraded for serious ROB, serious indirectness, and serious imprecision)
In-person Group
Parental emotion regulation | 1 RCT (336 patients) | Mothers 12 months postbaseline: (F(1, 230) = 4.43, p < 0.05); for fathers, the results were not significant | Low certainty; (downgraded for serious ROB, and serious indirectness)
Parental emotion regulation | 1 observational study (107 patients) | Emotional responsiveness: Change in R^2 = 0.09, p < 0.05; Positive affect effect: change in R^2 = 0.02 p > 0.05; Withdrawn: R^2 = 0.00 p > 0.05; Irritability: change in R^2 = 0.04, p > 0.05 | Very low certainty; (downgraded for serious ROB and serious imprecision)
In-person Individual
Family functioning/conflict | 1 observational study (3,499 patients) | Decrease in unhealthy family functioning: (0.19 ± 0.01, p < 0.0001) | Very low certainty; (downgraded for serious ROB and serious indirectness)
Virtual Home Visitation Live Coaching
Family functioning/conflict | 1 observational study (22 patients) | Family functioning t test 2.41 (p = 0.03), X^2^=2.15, d = 0.53 | Very low certainty; (downgraded for serious ROB, serious indirectness, and serious imprecision)
Virtual Individual Counseling
Family functioning/conflict | 1 RCT (349 patients) | Dysfunctional parenting: Change from baseline to 12 months = 1.12, d = 0.20, p > 0.05; Observed parent affect and behavior change from baseline to 12 months: −0.38, d = 0.39, p < 0.001 | Moderate certainty; (downgraded for serious indirectness)

KQ4 Key Findings: Characteristics of Effective Parenting Programs

In total, 71% (6 of 8 studies) demonstrated significant improvements in parenting skills. The majority of these studies were conducted among families with a parental history of SMI (N = 5). Half of the identified effective programs were delivered in person. Group-based formats were also the most common mode of intervention delivery. Only 2 programs involved direct interactions with the child during portions of the parenting program. Generally, adherence was high for the interventions delivered in person, with both group-based interventions having participation rates of over 70%. In studies that assessed participant satisfaction, ratings were all very favorable.

## CLINICAL AND POLICY IMPLICATIONS

Effective parenting interventions benefit not only parents but also children and families as a whole. Given that parent-child interactions are reciprocal, in that parental mental health impacts children and children’s emotions and behaviors impact parents, parent-focused programs are best viewed from a family-system perspective. VHA service expansion to integrate spouse caregivers into service provision provides evidence of the acknowledgement of a family-systems perspective to enhance capacity directly for the Veteran. Use of a well-established parenting intervention—such as Triple P, the most commonly used parenting intervention in the reviewed studies—is most likely to yield significant outcomes. Adapting these programs for Veteran parents who are vulnerable to high levels of stress could be a beneficial way to target specific population needs while building off proven strategies.

Parenting skills programs will be most beneficial when parents engage in the parenting program and practice positive parenting skills with their children.^58^ Further, programs require a commitment of time (eg, at least weekly sessions for 8-14 weeks in the reviewed studies). As such, accessibility and adherence are key factors to consider. Although no specific intervention format proved to be most beneficial in our review, the VHA should consider delivery methods that work best for busy families managing additional challenges such as parent mental illnesses, reintegration stressors, and traumas or moral injuries from experiences during military service.^59,60^ Though telehealth sessions can have drawbacks (eg, they require a stable internet connection), virtual sessions have shown comparable outcomes to in-person parenting programs and may allow for greater accessibility and flexibility^61,62^: families can join without having to take time off work, arrange childcare, or travel to VHA offices, and additional family members can join and learn the parenting skills. Group-based services also offer a way to provide a service efficiently to more individuals,^63^ and the effectiveness of group interventions was supported by our findings. Another potential benefit of group-based parenting interventions is that they may offer participating parents a broader network for social support from Veteran peers.

Given the high demand for mental health services among Veterans and the broader community, VHA can also consider the level of training needed to deliver effective parenting programs. For example, training peer facilitators in manualized parenting skills interventions expands the workforce of individuals who can provide this service. Also, use of peer interventionists can increase parenting program adherence. In one of the effective group-based interventions included in this review (ADAPT parenting program^47^), use of military-connected facilitators significantly improved engagement in the parenting programs. Veteran peer support specialists are currently employed by the VHA in mental health settings. These Veterans are trained to use their lived experience of mental health recovery to help patients with mental health concerns. Similarity, Veteran peer facilitators could be trained to provide evidence-based, manualized behavioral parenting programs within the VHA. Community care options could also be made available to Veterans and their families; yet many community parenting programs are oversubscribed, which could impact access to programs outside the VHA.^64^ Additional drawbacks of community-based programs include disconnect from ongoing care provision at the VHA, as well as the possibility that these community programs may not be well attuned to the unique parenting needs of the Veteran population.

While self-directed online programs are a promising approach, the 3 included in this review demonstrated mixed results. In several of the studies included in this review, self-directed parenting programs served as the comparison condition and produced small impacts on promoting positive parenting practices or child behaviors.^44,47^ Recent studies have empirically tested facilitated versus self-directed variants of Triple P and found that facilitated models significantly improve participant satisfaction, engagement and program completion, and parent and child outcomes.^65^ Together, these findings suggest that parenting programs that provide guidance and support are needed to develop the competencies and confidence to improve parent, child, and family outcomes. Results from KQ4 underscore that even among families with additional stressors (eg, parents with SMI, military-connected families), behavioral parenting programs can significantly improve parenting skills. These interventions do not need to directly engage with children to improve outcomes and can be offered in flexible group or virtual formats with facilitated engagement to offer support and guidance.

## PRIOR SYSTEMATIC REVIEWS

Several prior systematic reviews provide additional context for our findings. Waldrop et al^66^ completed a systematic review of 11 studies examining the effectiveness of parenting interventions aimed at improving maternal-child interaction to understand if these interventions also address mental health symptoms (ie, depression, anxiety, stress) in mothers. Ultimately, the study found mixed results that parenting interventions improved maternal mental health symptoms for depression, anxiety, or stress.^66^ Our review did not have parental mental health as an outcome of interest. Notably, the review by Waldrop et al did not identify any overlapping included articles with the results from our review. This is likely due to the differences in eligible study designs, interventions, and outcomes of interest. Specifically, our outcomes of interest were not limited to outcomes in the mother; we were also interested in parent, child, and family outcomes as well as intervention-related outcomes.

Including 18 studies, a systematic review by Branco et al^67^ sought to identify studies of group-based structured parenting programs published between the years 2015 and 2019. This review limited the publication years because it was an update of a previous review.^68^ They identified 14 unique parenting programs in a variety of high-, middle-, and low-income countries, with a substantial number of parenting programs in low-income countries as compared to the original systematic review.^69^ Our review was limited to OECD countries, since results from reviews performed in OECD countries may be most applicable to findings in the United States. Like our review, Branco et al^67^ reported that the majority of studies that assessed child outcomes improved problematic child behaviors. Also like our review, it showed promising results for group-based parenting programs globally, especially in the growing literature from low-income countries. These previous systematic reviews^66,67,70^ provide important context for our review by indicating how broad and nuanced the exploration of the effectiveness of behavioral parenting programs can be. It is important to note that while these reviews generated unique findings, there was no overlap in included studies, which demonstrates the distinctiveness of our review. As such, our review expands upon previous systematic reviews to build important new insights regarding interventions to improve parenting outcomes among 2 key populations: (1) parents with additional stressors associated with parental histories of SMI or adult sexual trauma and (2) parents who served in the military.

## LIMITATIONS

Our review has several strengths, including a protocol-driven design, a comprehensive search designed in collaboration with an expert search librarian, inclusion of broad study designs, and careful quality assessment via established ROB tools. Both our review and the literature, however, have limitations. Overall, the number of identified studies for many outcomes was small, and most of the literature had design limitations that impacted study quality. We identified no studies conducted among populations with a history of adult sexual trauma, a key interest of the VA nominating partners. Further, while we conducted careful narrative synthesis, it is difficult to discern patterns in interventions with limited numbers of studies across any outcome. Other limitations are detailed below.

### Publication Bias

Given the small number of studies, statistical methods to detect publication bias are not useful. Another strategy, such as searching ClinicalTrials.gov for completed but unpublished studies, is not a particularly effective way to identify publication bias.^71^ Thus, we did not conduct formal publication bias analysis.

### Study Quality

We were also limited by the existing literature. While we identified 7 RCTs, only 1 was low ROB. The remaining studies were nonrandomized designs, with nearly half having significant ROB considerations. Inadequate measurement and adjustment for key confounding variables, sample section, and missingness impacted judgments of higher ROB across included studies.

### Heterogeneity

Behavioral parenting programs are a complex health intervention, which has intrinsic heterogeneity. This review included RCTs and a wide variety of observational study designs. Moreover, we included a variety of intervention types that ranged from highly individualized virtual home visit models with high degrees of child involvement to in-person multifamily groups that were led by peer facilitators with no direct child engagement. Further, we sought to synthesize information across 3 levels of outcomes (parent, child, family) encompassing 8 unique outcomes. Studies varied considerably in their measurement of these 8 outcomes (eg, researcher observations vs self-reports) and the methods used to test intervention effects. We sought to address this fundamental heterogeneity by clustering our narrative synthesis by type of outcome and then by intervention approach. Further, we gave more conceptual weight to higher quality designs to prioritize evidence from those studies.

### Applicability of Findings to the VA Population

Of the 14 included studies, 5 were conducted among military-connected families, which makes them more applicable to Veterans than studies in the general population of civilians. Yet only one of these studies was conducted solely among Veterans. The other 9 were conducted in populations with SMI. For our review, we defined SMI broadly, including studies that were conducted in populations selected for PTSD, to increase applicability to the Veteran population. While we did not identify any studies conducted only among parents with PTSD, the majority of parents in the included studies for KQ2 were selected based on histories of MDD, a highly prevalent mental health condition. Depression is one of the most common mental health conditions among Veterans. We did not identify any studies that were designed for parents with a history of sexual trauma, which is a common trauma among women Veterans. As stated above, we limited eligibility to studies conducted in OECD countries, which improves applicability to the VHA. Taken as a whole, findings presented here likely have applicability to Veteran populations seeking care through the VHA.

### Recently Published Studies and Ongoing Work

We also identified 2 studies published after we concluded our search. The first was a VHA-based uncontrolled before-after pilot study of Strength at Home–Parents (SAHP), a trauma-informed parenting program, conducted among 21 Veterans with elevated PTSD symptoms.^72^ The intervention consisted of 8 group sessions separated by gender to accommodate any participants who may have experienced MST and, consequently, may be uncomfortable in mixed-gender groups. The in-person sessions were planned for 2 hours and integrated trauma-informed relationship improvement treatments^73^ with content to address aspects of parenting impacted by PTSD symptoms (eg, attachment, positive parenting behaviors) and education on child development, emotion regulation, and communication skills. Results provide evidence to support a high degree of satisfaction, credibility, and acceptability of the intervention among Veteran participants. While not designed to test the impact of the intervention on effectiveness targets, preliminary results suggest improvements in parenting practices and family functioning.

We also identified a second uncontrolled before-after study conducted with 111 mothers engaged with family preservation services in New York City.^74^ While not selected for histories of trauma, all participants met diagnostic criteria for PTSD. The intervention consisted of 23 sessions of weekly individual therapy that integrated evidence-based interventions: Skills Training in Affective and Interpersonal Regulation (STAIR; 9 sessions infused with parenting skills building), trauma-focused narrative therapy (6 sessions), and Parent-Child Care (PC-CARE; 8 sessions of a dyadic play therapy between the mother and child). Results suggest that the intervention is feasible. In a completers analysis of 70 mothers, significant changes post-intervention were observed for parenting stress, parenting skills, and child behaviors, as well as maternal PTSD and depression.^74^ An RCT of this intervention is underway and is slated for completion in 2025 (ClinicalTrials.gov identifier: NCT04752618).

It is important to note that the Parenting STAIR intervention assessed in this uncontrolled before-after study differs from the Parenting STAIR intervention piloted in the VA. First, the Parenting STAIR assessed with mothers in New York City was 23 sessions compared to a range of 12 to 17 sessions of Parenting STAIR piloted in the VA. Next, these programs differed in content as well. The community Parenting STAIR integrated parenting skills into STAIR from the first session and included an additional trauma-focused approach (6 sessions of narrative therapy). In contrast, the Parenting STAIR program piloted in the VA offered 5 sessions of evidence-informed parenting skills training to Veterans who completed the course of Skills Training in Affective and Interpersonal Regulation. Last, the community Parenting STAIR intervention directly involved children in the intervention via 8 sessions of evidence-based parent-child play therapy; this component is not a part of Parenting STAIR piloted in the VA.

To project forthcoming evidence from currently active studies in this area, we conducted a rapid review of ClinicalTrials.gov to identify studies in active recruitment, those not yet recruiting, or those that were closed but that do not yet have evidence of related publications. We identified only 2 ongoing studies that may be applicable to this review. Both are currently recruiting participants. The first study is an RCT (projected sample size: 20 to 40 parents) assessing a group-based parenting program augmented with 2 individual sessions among parents with clinically elevated depressive symptoms (ClinicalTrials.gov identifier: NCT04298437). To be eligible for this study, children must also have clinically elevated emotion regulation or behavioral issues. The other study is a variant of the FOCUS-EC intervention, an individual family therapy intervention with children involved in 2 of the 8 weekly therapy sessions, included in our review.^45^ Unlike the FOCUS-EC intervention included here among active duty military-connected families, this study is being conducted with 60 families with a parental history of interpersonal child trauma (ClinicalTrials.gov identifier: NCT05264415).

## RESEARCH GAPS/FUTURE RESEARCH

This comprehensive review of the literature identified several gaps in the current evidence that warrant future investigation. To inform future work in this area, we consider the PICOT framework (Table 9). This approach considers the population, intervention, comparator, outcome, and timing (PICOT) to identify gaps.

Table 9 Evidence Gaps for Parenting Skills Training on Key Outcomes

PICOTS Domain | Evidence Gap/Area for Future Exploration
Population | - Parents with histories of military sexual trauma and adult sexual trauma; - Parents with histories of PTSD; - Parents with mixed populations of SMI conditions; - Veterans with children under the age of 18
Intervention | - Peer-to-peer individual approaches; - Peer facilitator-led groups; - Interventions that assess the minimum amount of facilitated engagement needed to improve key outcomes (eg, self-directed + some group or individual support)
Comparator | - Head-to-head comparisons of virtual vs in-person modes; - Direct comparison of peer-led versus provider-led parenting groups; - Direct comparison of the additive effects of direct child involvement
Outcomes | - Parental knowledge; - Parental stress; - Parental emotion regulation; - Family conflict and overall family functioning; - Participant satisfaction
Timing | - Outcomes beyond 12 months to assess sustainment of key parent, family, and child outcomes

## CONCLUSIONS

The current systematic review sought to synthesize the effectiveness of parenting programs among parents with stressors due to parental history of sexual trauma and/or SMI, as well as among parents with histories of military service. We also sought to clarify the characteristics of effective programs—including the content and format of delivery—to inform implementation considerations for the VHA. Though the evidence base for parenting skills training to increase parenting competence and reduce family stress is robust in community samples, our review identified only 14 studies conducted among our populations of interest. Most of the studies identified in this review reported significant improvements on prioritized parent, child, and family outcomes, showing a general pattern of improvements across diverse types of parenting skills training programs that mirror findings in other studies of parenting programs.^1,67^ Yet certainty of evidence ratings were generally low due to issues with risk of bias of included studies or indirectness of populations or intervention approaches to the VA health care context. When evaluating parenting skills training programs, it is important to consider the feasibility and scalability of implementation across the VHA.