# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (see Appendix B for full list of excluded studies).

Figure 1 Literature Flowchart

## LITERATURE OVERVIEW

We identified 10,587 studies through searches of MEDLINE (via Ovid), EMBASE (via Elsevier), APA PsycINFO (via Ovid), and CINAHL Complete (via EBSCO). After removing duplicates, and including 1 citation identified by expert recommendation, there were 5,394 articles remaining in total. After applying inclusion and exclusion criteria to titles and abstracts, 110 articles remained for full-text review. Of these, we retained 28 articles, encompassing 14 unique studies, for data abstraction. Of these 14 studies, half were RCTs, and most were conducted in North America (USA, Canada). Table 2 provides an overview of study characteristics.

Table 2 Profile of Included Studies

Number of Studies | 14 studies (encompassing 28 articles)
Key Question | KQ1 (N = 0); KQ2 (N = 9); KQ3 (N = 5); KQ4 (N = 6)
Study Designs | Randomized controlled trial (N = 7), controlled before-after (N = 3), repeated measure studies (N = 2), uncontrolled before-after (N = 2)
Study Year Range | 2003 to 2022
Number of Participants | 4,172
Countries | USA (N = 6), Europe (N = 5), USA and Japan (N = 1), Canada (N = 2)
Intervention Categories | In-person individual (N = 1), in-person individual + group (N = 1), group-based in-person (N = 5), group-based chat only (N = 1), home-based (N = 1), web-based self-directed (N = 3), virtual individual counseling (N = 1), virtual individual home visitation with live coaching (N = 1)
Parent Outcomes | Self-efficacy (N = 5), parenting skills (N = 9), parental stress (N = 3), emotion regulation (N = 2)
Family Outcomes | Family functioning (N = 8), family conflict (N = 2)
Child Outcomes | Child behavior problems (N = 10)
ROBINS I Risk of Bias | Low (N = 0), moderate (N = 4), serious (N = 3), critical (N = 0)
ROB 2 Risk of Bias | Low (N = 2), some concerns (N = 2), high (N = 3)

## KEY QUESTION 1 AMONG PARENTS WITH A HISTORY OF SEXUAL TRAUMA, WHAT ARE THE EFFECTS OF PARENTING SKILLS TRAINING INTERVENTIONS ON KEY PARENT, FAMILY, AND CHILD OUTCOMES?

We identified no eligible studies that addressed KQ1.

## KEY QUESTION 2 AMONG PARENTS WITH A HISTORY OF SERIOUS MENTAL ILLNESS, WHAT ARE THE EFFECTS OF PARENTING SKILLS TRAINING INTERVENTIONS ON KEY PARENT, FAMILY, AND CHILD OUTCOMES?

### Key Points

- In total, 9 studies (N = 904 families) meeting eligibility criteria assessed the impact of parenting skills training programs among parents with histories of SMI. Most studies had fewer than 100 families/participants.
  ○ Study designs include the following: 5 RCTs (3 with high ROB), 2 controlled before-after designs (moderate ROB), 1 repeated measures design (serious ROB), 1 uncontrolled before-after study (moderate ROB).
  ○ Studies recruited parents with the following conditions: MDD (3 studies N = 445), schizophrenia spectrum disorder (2 studies, N = 141 parents), bipolar disorder (3 studies, N = 230), and mixed populations of SMI conditions (1 study, N = 48 parents).
- The most common intervention mode was in-person multi-family groups (4 studies), followed by web-based self-directed modules (3 studies).
  ○ Most studies (N = 6) cited an evidence-based parenting skills protocol as the basis for their parenting skills training approach.
  ○ Of the 5 studies delivered in-person, most (N = 4) directly involved the child as part of the parenting skills training program.
- Parent-level outcomes: Eight studies assessed parenting outcomes. While the overall trend was toward positive improvements in key parent outcomes, not all were significant.
  ○ The overall trend supported a positive impact of behavioral parenting programs on the outcome of parenting skills (results from 5 of 7 studies were significant), although a meta-analysis of 3 web-based self-directed programs was not significant. None of the web-based studies sought to include other family members like spouses or children.
  ○ Most studies measuring parental self-efficacy (3 of 5 studies) reported significant increases in parents’ sense of competency in parenting.
  ○ Only 1 study assessed stress related to parenting; results demonstrated significant improvements in parental stress.
  ○ No identified studies assessed parental emotion regulation and parenting knowledge among parents with histories of SMI.
- Family-level outcomes: Five studies measured family functioning and 1 measured family conflict. The studies show mixed results in family functioning outcomes.
  ○ Only 2 of the 5 studies reported significant improvements. Both studies were in-person multi-family parenting groups.
- Child-level outcomes: Child problem behaviors were assessed in most studies (N = 7); results were mixed.
  ○ All 4 studies of the parenting skills programs that reported significant impacts on child behaviors were adapted from evidence-based parent programs.
  ○ The positive studies used 3 different interventions: in-person family counseling plus multi-family group sessions with parallel but separate group sessions for children (1 study), a home-based program (1 study), and a web-based self-directed program (2 studies).

### Detailed Description

We identified 9 studies^29–38^ (N = 904 families) that met our inclusion criteria for behavioral parenting programs conducted among parents with histories of SMI. Most of the studies were conducted in samples of less than 100 families, with 3^29,33,35^ being conducted in studies of less than 50 participants. Studies recruited parents with the following conditions: MDD (3 studies,^34–36^ N = 445), schizophrenia spectrum disorder (2 studies,^29,32^ N = 141), bipolar disorder (3 studies,^30,31,37^ N = 230), and mixed population of SMI conditions (1 study,^33^ N = 48).

Parenting programs used 4 main intervention modes: in-person multi-family groups (4 studies^30,34–36^), in-person home visits with a self-directed workbook (1 study^29^), an online chat-based group (1 study^33^), and web-based self-directed modules (3 studies^31,32,37^). Most studies (N = 6) did not directly involve the child as part of the parenting skills training program. For synchronous parenting skills interventions, sessions ranged in length from 45 minutes to 2 hours over the course of 8 to 14 weeks. Studies employed a mix of interventionists, with only 2 using licensed providers^35,36^ and 3 using graduate students^29,30,34^ supervised by clinical psychologists. The 3 self-directed internet-based studies ranged in length from 10 to 16 weeks. Appendix D provides further details of each included intervention.

Study designs include 5 RCTs,^31,32,34,35,37^ 3^32,35,37^ of which had high ROB.^30,33,35^ Two studies^30,36^ were controlled before-after designs (moderate ROB), 1^29^ study used a repeated measures design with serious ROB, and 1 was an uncontrolled before-after study with moderate ROB.^33^ Sources of bias among the RCTs identified for this KQ included deviations of intended interventions, missing outcome data, and outcome measures. Common ROB for the other studies identified for KQ2 included confounding, selection of participants into the study, missing data, and outcome measures. (Refer to Appendix F for details of the ROB assessments.)

Due to the heterogeneity in study designs and outcomes, we were able to conduct only 1 meta-analysis. Other outcomes are narratively synthesized. Next, we describe the results for each category of outcomes by intervention type.

### Parent-level Outcomes

Eight studies assessed at least 1 parenting outcome of interest. Of these, 7 assessed parenting skills, 5 examined parental self-efficacy, and 1 focused on parental stress. No studies assessed the impact of parenting skills programs among parents with SMI on the outcomes of parental emotion regulation and parenting knowledge. Parent-level outcomes are organized by parenting skills, parenting self-efficacy, and parental stress and further refined by intervention type.

#### Parenting Skills

The 7 studies that assessed the outcome of parenting skills included 4 RCTs (3 high ROB^32,35,37^, 1 low ROB^31^), 1 uncontrolled before-after study,^33^ 1 controlled before-after study,^30^ and 1 repeated measures study.^29^ Most studies (5 out of 7) reported a significant impact of the parenting skills training interventions on parenting skills.^29,30,32,33,37^ Below, we summarize results by intervention type, focusing first on randomized designs, followed by those with fewer ROB concerns.

##### Group-based interventions

One RCT (high ROB),^35^ 1 controlled before-after study (moderate ROB),^30^ and 1 uncontrolled before-after study (moderate ROB)^33^ assessed the impact of parenting skills training programs on parenting skills using group sessions. Two of these were in-person groups and reported mixed results, and 1 was conducted in an online secure chat room and reported positive results on parenting practices.

The RCT assessed the impact of an intervention consisting of 8 weekly multi-family group 2-hour sessions that took place in person compared to a waitlist control among 44 parents with major depressive disorder and found no significant difference using the Positive Parenting Practice Scale.^35^ The controlled before-after study assessed the impact of weekly group sessions spread out over 12 weeks that focused on strengthening stress-coping and resilience among parents with bipolar disorder.^30^ Sessions were 2 hours and after completing the session participants were given the opportunity to practice their skills related to problem solving and healthy communication. This study reported significant differences in observed negative parental behaviors (p < 0.001) and positive parental behaviors (p < 0.001).

The uncontrolled before-after study enrolled 48 parents with a broad range of SMI conditions and assessed the impacts of an online intervention consisting of 8 90-minute weekly group sessions for parents only that took place in a secured online chatroom.^33^ Participants were given homework and practice exercises to complete between session. This study used a Dutch version of a parenting scale and reported positive impacts and a moderate-sized effect on the parental laxness subscale (SMD = 0.52, p = 0.007). For the over-reactivity subscale, the study reported a significant difference and a large effect size (SMD = 2.76, p = 0.004).

##### Web-based self-directed interventions

Three RCTs^31,32,37^ assessed the impact of self-paced online programs on parenting skills. The first RCT (low ROB)^31^ analyzed 97 parents diagnosed with bipolar disorder who were randomized into an intervention group or a waitlist control group. In the intervention group, participants were offered access to interactive self-management educational material focused on bipolar disorder as it relates to parenting issues for 16 weeks. The second RCT (high ROB)^37^ analyzed 39 parents with self-diagnosed bipolar disorder who either (a) received a 10-week, web-based intervention focused on managing child behavior plus a listserv moderated by a parent with mental illness and a mental health provider or (b) were randomized to a waitlist control condition. During the intervention course, new web-based information was released to parents weekly in written, video, and audio formats to help them complete their self-help book. In the final RCT (high ROB),^32^ 60 mothers diagnosed with either schizophrenia or a mood disorder were randomized to receive either an intervention consisting of a self-guided, online parenting course or a control condition involving participation in a healthy lifestyle course. In the intervention condition, mothers were instructed to complete weekly 30-minute online sessions for 3 months; each lesson had a short quiz and homework assignment. While negative parenting practices were reduced across the 3 self-directed studies (N = 168), web-based interventions did not significantly impact negative parenting practices (SMD = −0.44, 95% CI [−1.33, 0.45]; 95% prediction interval [PI] [−1.84, 0.92]) (Figure 2).

Figure 2 Forest Plot of the Effects of Web-based Self-directed Interventions on Parenting Skills at End of Treatment

##### Home-based self-help workbook with facilitated engagement interventions

One repeated measures study (serious ROB) assessed the delivery of a 10-week manualized self-help workbook of the Triple P parenting program for 10 parents diagnosed with schizophrenia.^29^ Participant difficulty in implementing the workbook necessitated a change to a facilitated model; study staff visited participants’ homes to help with the weekly lessons. Specifically, parents had difficulty understanding tasks in the workbook and required support and guidance in developing plans to implement parenting skills. Additionally, facilitated home-based sessions with role play gave participants the opportunity to practice the skills they were learning in the manual. The Total Parenting Scale was used to assess a range of parenting behaviors and demonstrated large, significant effect sizes at both 3 (SMD = 2.76, p = 0.004) and 6 months (SMD = 3.28, p = 0.003) after baseline.

#### Parenting Self-efficacy

In total, 5 studies assessed sense of competency in parenting (ie, parental self-efficacy). This included 3 RCTs (2 high ROB,^32,35^ 1 low ROB^31^), 1 uncontrolled before-and-after study^33^ with moderate ROB, and 1 repeated measures study^29^ with serious ROB. While reports were mixed by intervention type, most studies (3 of the 5) reported a significant impact on parenting self-efficacy.

##### Group-based interventions

One high ROB RCT^35^ and 1 serious ROB uncontrolled before-after study^33^ assessed the impact of parenting skills training programs on self-efficacy for parenting. The RCT found that an in-person multi-family group program (8 weekly 2-hour meetings) did not significantly impact self-efficacy (p = 0.06) compared to waitlist control among 44 parents with major depressive disorder. In contrast, the uncontrolled study reported moderate effects of an online program conducted in a secure group chat room consisting of 8 weekly sessions lasting 90-minutes (SMD = 0.46, p = 0.009) for 48 parents with a diagnosis of SMI.

##### Web-based self-directed interventions

Two RCTs assessed the impact of self-paced online programs on parental self-efficacy. The first RCT (N = 97; low ROB)^31^ found that 16 weeks of the web-based Triple P Positive Parenting Program^39,40^ resulted in significant improvements in parenting confidence for parents with bipolar disorder, compared with waitlist control (p < 0.01). The other RCT (high ROB)^32^ assessed web-based self-directed programs plus a listserv moderated by parent and a mental health professional among 60 mothers diagnosed with a schizophrenia spectrum or mood disorder and did not find a significant impact on confidence in parenting.

##### Home-based self-help workbook with facilitated engagement interventions

In a repeated measures study (serious ROB)^29^ of 10 mothers with schizophrenia spectrum disorder, a self-help variant of the Triple P Positive Parenting Program^39,40^ was implemented with in-person guidance and support from study staff over 10 weeks. This study reported significant impacts on parental self-efficacy 3 months after baseline (SMD = 2.49, p = 0.001).

#### Parental Stress

##### Web-based self-directed interventions

Parental stress was reported by the low ROB RCT that delivered 16 weeks of the Triple P Positive Parenting program to 97 parents with bipolar disorder.^31^ Parenting stress showed significant improvement post intervention compared with waitlist control (p = 0.01).

### Summary of Parent-level Results

The included studies show mixed results in parent-level outcomes. Still, the overall trend was toward positive improvements in key parent outcomes. Of the 7 studies that reported on parenting skills, 5 demonstrated significant impacts. Similarly, most studies measuring parental self-efficacy also reported significant increases in parents’ sense of competency in parenting. While only 1 study assessed stress related to parenting, this study also reported significant improvements in parental stress. No clear pattern emerged across intervention types, likely due to differences within each of the intervention types based on dose, populations, and intervention content.

#### Family-level Outcomes

In total, 5 of the 9 studies assessed at least 1 family-level outcome: 5 measured family functioning and 1 measured family conflict. Family-level outcomes are organized by family functioning and further refined by intervention type.

##### Family Functioning

In total, 5 studies assessed family functioning. This included 3 RCTs (2 high ROB;^32,35^ 1 low ROB^31^) and 2 controlled before-after studies^30,36^ (moderate ROB). Only 2 studies^30,35^ reported a significant impact of the parenting skills training interventions on improved family functioning.

###### Group-based interventions

Three studies assessed the impact of parenting interventions that used a multi-family group mode: 2 moderate ROB controlled before-after studies^30,36^ and 1 high ROB RCT.^35^ In the RCT, 44 parents with MDD were randomized to 8 weeks of in-person multi-family parenting training or a waitlist control. At end of treatment, parents in the multi-family group reported significant improvement in family functioning (p < 0.05) and positive trends in family conflicts and parental disagreements that did not reach statistical significance.

The 2 controlled before-after studies both added a separate, parallel children’s group to the multi-family group parenting program; results were mixed. The first controlled before-after study^30^ assessed 12 weekly sessions among 55 parents with bipolar disorder. Using video recordings of structured parent-child cooperation tasks, the intervention demonstrated positive improvements in family functioning at end of treatment (p = 0.005) that persisted to 6 months post-treatment (p < 0.001). The other controlled before-after study^36^ assessed a 10-week intervention consisting of in-person family counseling plus multi-family group sessions with parallel but separate group sessions for children for 175 parents with MDD. While the intervention group resulted in child-reported improvements in family functioning, these improvements did not significantly differ between groups.

###### Web-based self-directed interventions

Two RCTs assessed the impact of a web-based self-directed parenting program and found no significant impacts on family functioning. The first study^31^ (low ROB) assessed the impact of parents randomized to a 16-week online Triple P program or waitlist among 97 parents with bipolar disorder. The other RCT^32^ (high ROB) randomized 60 mothers with schizophrenia spectrum disorder to 3 months of an online self-directed parenting program plus a moderated listserv.

### Summary of Family-level Results

The included studies show mixed results in family-level outcomes. While all studies yielded improvements in various measures of family functioning, only 2^30,35^ of the 5 studies reported significant improvements. Both studies were in-person multi-family parenting groups, with 1 also having a children’s group component.^30^

#### Child-level Outcomes

Among parents with a history of SMI, 7 of 9 studies explored the impact of parenting skills training programs on child behavioral problems. These included 3 RCTs (1 high ROB,^37^ 1 low ROB,^31^ 1 with some concerns ROB^34^), 2 controlled before-after studies (both with moderate ROB),^30,36^ 1 uncontrolled before-after study^33^ (moderate ROB), and 1 repeated measures study (serious ROB). Child-level outcomes are further refined by intervention type.

##### Child Behaviors

###### Group-based interventions

One RCT (some concerns for ROB),^34^ 2 controlled before-after studies (moderate ROB),^30,36^ and 1 uncontrolled before-after study (moderate ROB)^33^ assessed the impact of parenting skills training programs on child behavioral problems. Of these, 3 studies assessed in-person groups, with only 1 controlled before-after study^36^ reporting significant effects. In this moderate ROB controlled before-after study, 175 parents with MDD were assigned to a 10-week intervention consisting of in-person family counseling plus multi-family group sessions with parallel but separate group sessions for children. Child behavioral outcomes were assessed using children’s and parents’ reports of children’s emotional and behavioral problems as outcomes as well as 5 indices of parent-child relationships. Follow-up assessments indicated significantly lower levels of children’s emotional and behavioral problems at post-test according to self-report (SMD = 0.40, p < .01) and parental report (SMD = 0.37, p < .01). The last study, an uncontrolled before-after design,^33^ assessed an online parenting program that used a secure chat room and reported no significant differences in parent reports of child problem behaviors.

###### Web-based self-directed interventions

Two RCTs assessed the impact of a web-based self-directed parenting skills program; both studies reported significant impacts on child problem behaviors. The first RCT (low ROB)^31^ tested the impact of parents randomized either to either a 16-week online Triple P program or a waitlist among 97 parents with bipolar disorder. This study reported a significant difference in parent reports of child behavioral problems favoring the intervention (p < 0.01) that persisted through 48-week follow-up. The other RCT (high ROB),^37^ also among parents with bipolar disorder (N = 78), reported a large-sized effect at end of treatment (SMD = 1.00, p < 0.004).

###### Home-based self-help workbook with facilitated engagement

In a serious ROB repeated measures study^29^ of 10 mothers with schizophrenia spectrum disorder, a self-help Triple P workbook^39,40^ was implemented with in-person guidance and support from study staff over a 10–week period. This study reported significant impacts on both intensity (SMD = 2.38, p = 0.001) and frequency (SMD = 2.71, p = 0.001) of problematic child behaviors at end of treatment that were sustained at 3- and 6-months’ follow-up assessments.

### Summary of Child-level Results

The included studies show mixed results regarding the impact of parenting skills training on children’s problem behaviors among parents with SMI. While all studies showed improvements, 4^29,31,36,37^ of the 7 studies reported significant improvements. The positive studies used 3 different interventions: in-person family counseling plus multi-family group session with a parallel but separate group session for children (1 study^36^), home-based program (1 study^29^), and web-based self-directed program (2 studies^31,37^). Of note, all 4 of the parenting skills programs that had significant impacts on child behaviors were adapted from 2 evidence-based parenting programs: Triple P^31,37^ (3 studies^29,31,37^) and Systematic Training for Effective Parenting^41^ (1 study^36^) (Table 3).

Table 3 Pattern of Outcomes Assessing Effectiveness of Parenting Skills Training Programs Among Parents With SMI

Intervention Type^a^ | Parent Outcomes | | | | | Family Outcomes | | Child Outcomes
Study | Parenting Skills | Parent Knowledge | Parent Self-efficacy | Parent Stress | Emotion Regulation | Family Functioning | Family Conflict | Child Behavioral Problems
KQ2: Populations With Parental Histories of Serious Mental Illness
Home-based Self-help Workbook With Facilitated Engagement
Wolfenden, 2022^29^
In-person Multi-family Group Intervention
Compas, 2009^34^,^b^
Sanford, 2003^35^,^b^
Serravalle, 2021^30^
Virtual Group-based Chat Intervention
van der Zanden, 2010^33^
Web-based Self-directed Intervention
Jones, 2015^37^
Jones, 2017^31^,^b^
Kaplan, 2014^32^/O’Shea, 2019^42^,^b^
In-person Individual Family Counseling + Multi-family Group + Children’s Group Intervention
Fernando, 2018^36^

Notes.

a Light blue shading indicates that an outcome was reported in the study. Dark blue shading indicates an outcome that was statistically significant.

b Randomized controlled trial study design.

## KEY QUESTION 3 AMONG PARENTS WITH A HISTORY OF MILITARY SERVICE, WHAT ARE THE EFFECTS OF PARENTING SKILLS TRAINING INTERVENTIONS ON KEY PARENT, FAMILY, AND CHILD OUTCOMES?

### Key Points

- In total, we identified 5 studies (N = 3,268 families; N = 4,772 participants) that assessed the impact of parenting skills training programs among families with a parental history of military service.
  ○ Only 2 studies were RCTs, of which only 1 was low ROB.
  ○ Only 1 study was conducted exclusively among Veterans (N = 41).
- Parenting programs were delivered by individual family therapy (2 studies); multi-family groups (2 studies); and virtual home visits with live coaching (1 study).
  ○ Nearly all interventions (4) directly involved children as part of the parenting skills training program.
  ○ All included studies cited an evidence-based parenting skills training program as the basis for their parenting intervention.
- Parent-level outcomes: Studies assessed these outcomes: parenting skills (1 study), 2 parental stress (2 studies), and parental emotion regulation (2 studies). No included studies explored parenting self-efficacy or parenting knowledge.
  ○ The overall trend was toward positive changes in parent outcomes, though not all were significant.
- Family-level outcomes: Only 3 studies assessed family functioning; no studies assessed family conflict.
  ○ The 2 nonrandomized designs reported significant impacts on family function, while the low ROB RCT demonstrated significant improvements for mothers but not for fathers.
- Child-level outcomes: Child behaviors were assessed in 3 studies. While all reported significant improvements in some aspects of child behaviors, 2 studies had serious ROB issues.

### Detailed Description

We identified 5 eligible studies^43–47^ (N = 3,268 families; N = 4,772 participants) that assessed the impact of parenting skills training interventions among parents with a history of military service. The median study size was 200 families (range: 41 to 2,615). Most studies were conducted among families with at least 1 active-duty parent (N = 3 studies^43,45,47^). One^44^ was conducted with families of active duty servicemembers or families with a Veteran parent with a history of deployments. Only 1 study was conducted exclusively with Veterans who were eligible to receive services through the VA (N = 41).^46^

Parenting programs used 3 main interventions: individual family therapy (1 in-person^45^, 1 via videoconferencing^43^), in-person multi-family groups (2 studies^44,47^), and virtual home visits with live coaching (1 study^46^). The number of sessions/visits ranged from 6 to 14, with a range in length from 60 minutes to 2 hours. All included studies used interventions adapted from evidence-based parenting skills training programs.

All but 1 intervention^47^ directly involved the child as part of the parenting skills training program. Child involvement was variable across studies. The 2 individual family therapy interventions^43,45^ had at least 2 sessions where children attended family therapy with the parent(s). An in-person multi-family^44^ group program had a separate children’s play group held concurrently during parent sessions. One study included observed parent-child interactions by videoconference platform and interventionist real-time feedback via a “bug in ear” system.^46^

Nearly all (80%) of the studies employed a licensed provider to implement the parenting skills training interventions, with most (N = 3) using a master’s-level clinician. One study^47^ employed a mix of non-clinical facilitators, including National Guard service members and Veterans. Appendix D provides further details of each included intervention.

Study designs include 2 RCTs^43,47^ (1 low ROB,^43,47^1 with some ROB concerns^43,47^). Overall sources of ROB for RCTs included the randomization process, outcome measures, and selection of results reported. Nonrandomized designs include the following: 1 controlled before-after design^44^ (moderate ROB), 1 repeated measures design^45^ (serious ROB), and1 uncontrolled^46^ before-after study (moderate ROB). Sources of bias included confounding, missing data, and outcome measures. (Refer to Appendix F for details of the ROB assessments.)

Due to the heterogeneity in study designs, outcomes, and intervention types, we were not able to conduct meta-analysis. Other outcomes are narratively synthesized. Next, we synthesize the results for each category of outcomes by intervention type.

### Parent-level Outcomes

Included studies assessed these outcomes: parenting skills (1 study), parental stress (2 studies), and emotion regulation of the parent (2 studies). No studies assessed parenting self-efficacy and parenting knowledge. Parent-level outcomes are organized by parenting skills, parental stress, and parental emotion regulation and further refined by intervention type.

#### Parenting Skills

##### In-person multi-family group intervention

One RCT (rated as some concerns for ROB)^47^ tested parenting skills training interventions among 336 National Guard and Reserve families (N = 608 parents). Families needed to have at least 1 child aged 5–12 years and a parent with a deployment to Operation Iraqi Freedom, Operation Enduring Freedom, or Operation New Dawn (OIF/OEF/OND). Families were randomized to an in-person group-based parenting program (After Deployment, Adaptive Parenting Tools; ADAPT) modeled after the evidence-based parenting skills training program Parent Management Training–Oregon Model (PMTO)^48^ or a usual care condition of web and print resources on parenting. The core components of the PMTO model were extended to include (1) information specific to military families on deployments, (2) mindfulness exercises as a technique to improve parent emotion regulation, and 3) emotion coaching skills. The facilitators were a mix of non-military human service providers (eg, school guidance counselors) and Veterans and National Guard servicemembers who received 11 days of training and biweekly coaching from PMTO-certified staff. The intervention was deployed in 2-hour weekly sessions for 14 weeks. Children were not involved in the intervention, but 80% of families had 2 parents participating in the program. In an intent to treat analysis, controlling for observed baseline parenting skills, the ADAPT intervention resulted in increased effective parenting skills at 1 year compared to the usual care control (p = 0.01) with a moderate effect size (SMD = 0.35).

#### Parental Stress

In total, 2 studies assessed the outcome of parental stress: a low ROB RCT^43^ and a serious ROB^46^ uncontrolled before-after study. Both used a virtual implementation mode and included the child in the parenting skills training interventions. Results were mixed on the outcome of parental stress.

##### Virtual individual family therapy intervention

One low ROB RCT^43^ compared a trauma-informed family therapy program (Families OverComing Stress-Early Childhood; FOCUS-EC) among 200 military-connected families with young children (aged 3-6 years) who had at least 1 parent who had served post 9/11. FOCUS-EC is an adaptation of an evidence-based family-centered intervention, Families OverComing Stress (FOCUS), which has been implemented widely throughout US military installations.^45,49,50^ FOCUS-EC was delivered by a doctoral- or master’s-prepared mental health provider over videoconferencing and included 6 modules delivered in 60–90-minute sessions over 4–10 meetings. Children were involved in some portions of the virtual family counseling when modules were focused on skills practice and fostering emotion regulation though playtime, and most families (75%) had both parents participate in the program. Parents randomized to the control condition had access to an online parent education program. While the intervention did not significantly reduce parental stress compared to the control, parents in the FOCUS-EC reported greater reductions in PTSD symptoms at 6 months compared to the online parent education program (p < 0.05).

The other study to assess parental stress^46^ was an uncontrolled before-after study (serious ROB) among 41 Veterans with a child aged 3 to 9 years. The Online Parenting Pro-Tips (OPPT) program used web-based educational modules on child development, positive parenting skills, and challenges related to miliary families plus 6 60-minute psychotherapy sessions delivered by videoconferencing every 2 weeks by master’s-level social workers or counselors. About 30 minutes of these virtual sessions were devoted to therapist observations and live coaching via “bug in ear” feedback of Veteran and child interactions and produced significant reductions in parental stress at end of treatment (SMD = 0.98, p = .0003).

#### Parental Emotion Regulation

In total, 2 studies assessed the outcome of parental emotion regulation: an RCT (some concerns ROB) and a controlled before-after study (moderate ROB). Both used an in-person multi-family group and reported mixed results on parental emotion regulation.

##### In-person multi-family group intervention

The RCT of the ADAPT intervention^47,51^ (described above) conducted a secondary analysis to assess the impact of the parenting program on emotion regulation problems via pre-post ANCOVA models separately for mothers and fathers. Mothers randomized to the ADAPT intervention reported a small but significant impact on emotion regulation problems at 12 months post-baseline (p < 0.05). For fathers, the results were not significant. The other identified study to report on parental emotion regulation was a controlled before-after study (moderate ROB) among 76 military-connected families (activity duty and Veterans) with a history of deployments and with at least 1 child under the age of 8. The parenting intervention, “Strong Military Families,” was adapted from another parenting program for high-risk mothers.^52^ The Strong Military Families program consisted of 10 multi-family group sessions and up to 3 individual parent sessions over 10-12 weeks. Children participated in a concurrent playgroup, and group facilitators provided supported opportunities for parent-child interactions at the beginning and end of each session. Parents in the comparison condition were given a written self-help guide of the intervention. The multi-family group intervention resulted in significant improvements in some positive aspects of emotion regulation (positive affect: p < 0.05, emotion responsiveness: p < 0.05) but did not significantly impact expression of negative emotion regulation (eg, anger, irritability, withdrawal, hostility) as assessed by observations of parent-child interactions.

### Summary of Parent-level Results

The included studies show mixed results on key parent-level outcomes. For parenting skills, the only study that assessed this outcome demonstrated moderately sized improvements that were significant. Yet, for all other parenting outcomes, results were mixed either between studies (ie, 2 parental stress studies and only 1 reporting significant results) or within studies (ie, emotion regulation improved for mothers but not fathers; positive aspect of emotion regulation improved but negative aspects did not), which limits the strength of conclusions about program effects by different interventions.

#### Family-level Outcomes

In total, 3 of the 5 studies assessed family function, and no studies assessed family conflict. Family-level outcomes are organized by family functioning and further refined by intervention type.

##### Family Functioning

The 3 studies that assessed family functioning included an RCT of low ROB,^43^ a repeated measures design,^45^ and an uncontrolled before-after study^46^ (both serious ROB). These studies used 2 different intervention modalities: individual family counseling (2 studies; 1 virtual and 1 in-person) and virtual home visits with live parent coaching (1 study). All 3 studies directly involved children in some aspect of the parenting program. Both nonrandomized designs reported significant impacts on family function, while the low ROB RCT reported improvements for mothers only.

###### Individual family therapy intervention

One low-ROB RCT^43^ compared FOCUS-EC, a virtually delivered trauma-informed family therapy program (described above) among 200 military-connected families, to a control condition that had access to an online parent education program. While the FOCUS-EC intervention produced greater decreases in parent-child dysfunctional interactions via parent reports at all 3 assessments (3, 6, and 12 months), the results were only significantly improved for mothers at 12 months post-baseline. Fathers did not report significant differences in family functioning at any follow-ups compared to controls.

The other individual family therapy intervention^45^ used an in-person modality and was assessed via repeated-measures studies (serious ROB). This study was conducted through military installations in Japan and the United States among 2,615 unique families (N = 3,499 parents; 3,810 children) who had at least one child aged 3-17. The Families OverComing Under Stress (FOCUS) intervention was deployed through 8 sessions that ranged from 30-90 minutes and included a mix of parent-only (3 sessions), child-only (2 sessions), and family sessions (3 sessions) and was delivered by a master’s- or doctoral-level mental health provider. Overall, both civilian and military parents reported a decrease in unhealthy family functioning (p < 0.001) and lower odds of meeting the threshold for unhealthy family functioning (odds ratio [OR] = 0.50, 95% CI [0.43, 0.58]).

###### Family home visitation with live coaching intervention

The other study^46^ to assess family function was an uncontrolled before-after study (serious ROB) among 41 Veterans with a child aged 3–9 years. The OPPT intervention used a virtual home visits model with live parent coaching (described above) and reported significant reductions in family dysfunction at end of treatment (SMD = 0.53, p = 0.03).

### Summary of Family-level Results

Only 3 studies reported family functioning outcomes; these intervention approaches all directly involved children in the parenting program. These 3 studies reported significant impacts on family function. No studies assessed family conflict.

#### Child-level Outcomes

Three of the 5 studies identified assessed the impact of parenting skills training programs on child behaviors among military-connected families. These included 1 RCT^43^ (low ROB), 1 repeated measures study^45^ (serious ROB), and 1 uncontrolled before-after study^46^ (serious ROB). Child-level outcomes are further refined by intervention type.

##### Child Behaviors

###### Individual family therapy intervention

Two studies assessed the impact of individual family therapy on child behaviors. The first was a low ROB RCT^43^ that compared FOCUS-EC, a trauma-informed family therapy program (described above) among 200 military-connected families, to a control condition that had access to an online parent education program. Compared to an online parent education program, the FOCUS-EC intervention produced greater decreases in parental reports of difficult child behaviors at 12 months post-baseline (p < 0.01), though the effect size was small (SMD = 0.20). When parents were assessed separately, only mothers (N = 194) reported significant improvements in difficult child behaviors (SMD = 0.30, p < 0.05). Observational measures of child behaviors yielded similar results with FOCUS-EC demonstrating significantly greater increases in positive child behavior (SMD = 0.40, p < 0.01) in the total sample (N = 349), but these were only significant for mothers at 12 months (SMD = 0.42, p < 0.001).

The second individual family therapy intervention,^45^ FOCUS, used a repeated measures study design (serious ROB). This study was conducted through military installation with 2,615 unique families (3,499 parents; 3,810 children). Among all children, the odds of parent-reported child difficulties (OR = 0.22, 95% CI [0.19, 0.25]) and difficulties with pro-social behaviors (OR = 0.46, 95% CI [0.41, 0.52]) significantly dropped at 6-month follow-ups.

###### Family home visitation with live coaching intervention

The other study to assess the impact of parenting programs on child behaviors was an uncontrolled before-after study (serious ROB) among 41 Veterans with a child aged 3–9 years.^46^ The OPPT intervention used a virtual home visits model with live parent coaching. At end of treatment, parents reported fewer problem behaviors (SMD = 0.87, p = 0.03). Also, the frequency of clinically elevated parent ratings of problem behaviors (p = 0.02) and intensity of child behaviors (p = 0.03) showed significant improvement post-treatment.

### Summary of Child-level Results

Only 3 studies reported on the impact of parenting programs on child behaviors (Table 4). Children were directly involved in all interventions. All 3 studies reported significant impacts on child behaviors. Two studies had serious ROB considerations.

Table 4 Pattern of Outcomes Assessing Effectiveness of Behavioral Parenting Programs Among Military-connected Families

Intervention Type^a^ | Parent Outcomes | | | | | Family Outcomes | | Child Outcomes
Study | Parenting Skills | Parent Knowledge | Parent Self Efficacy | Parent Stress | Emotion Regulation | Family Functioning | Family Conflict | Child Behavioral Problems
KQ1: Populations With Parental Histories of Military Service
In-person Individual Family Intervention
Lester, 2016^45^
In-person Multi-family Group Intervention
Gewirtz, 2018^47^,^b^
Julian, 2018^44^
Virtual Individual Family Intervention
Mogil, 2021^43^,^b^
Virtual Family Home Visitation With Live Coaching Intervention
Riegler, 2020^46^

Notes.

a Light blue shading indicates an outcome was reported in the study. Dark blue shading indicates a statistically significant outcome.

b Randomized trial design.

## KEY QUESTION 4 WHAT ARE INTERVENTION CHARACTERISTICS (eg, FORMAT, DOSE, CONTENT) OF THE IDENTIFIED EFFECTIVE PARENTING SKILLS TRAINING INTERVENTIONS?

### Key Points

- Of the 8 studies that reported on impact of parenting training programs on the uptake of parenting skills, 71% (N = 6) demonstrated significant improvements in parenting skills.
  ○ The majority of these studies were conducted among families with a parental history of SMI (N = 5).
- Half of the identified effective programs were delivered in person. Group-based formats were the most common mode of intervention delivery.
- Only 2 of the 6 programs involved direct interactions with the child during a portion of the parenting program.
- All parenting skills interventions used manualized protocols.
  ○ Most programs incorporated homework assignments to reinforce parenting skills.
  ○ The most common areas covered in the parenting programs were discipline and behavior management strategies (5 studies) and fostering positive interactions with the child(ren) (5 studies).
- Adherence was high for the interventions delivered in person, with both group-based interventions having participation rates of over 70%.
  ○ Of note, use of a military-connected facilitator led to greater program participation (73.25% vs 59.78% of sessions) in 1 study.
  ○ In studies that assessed participant satisfaction, ratings were all very favorable.

### Detailed Description

Of the 8 studies that assessed parenting skills, 6 studies, representing a total of N = 658 families, reported significant changes in parenting skills. Only 1 of the 5 studies meeting eligibility for KQ3 (ie, families with a military history) assessed the impact of a parenting skills program on parenting skills; this study demonstrated a positive impact on uptake of parenting skills in an RCT^47,53^ of 336 families with at least 1 activity duty parent. Among the 9 studies meeting eligibility for KQ2 (ie, parental history of SMI), 7 assessed the impact of the parenting training program on parenting skills. Of these 7 studies, 5^29,30,33,37,38,42^ (71%) reported significant effects of parenting training programs on positive parenting skills among parents with a history of serious mental illness: 3 RCTs, 1 controlled before-after study, 1 uncontrolled before-after study, and 1 repeated measure study. Three studies were found to be some concerns/moderate ROB,^30,33,38,54^ and 3 serious/high ROB^29,32,37^ (designation term depending on instrument used). Common sources of ROB for RCTs relevant to this KQ included issues with randomization, outcome measures, and selection of results reported. For other study designs, sources of bias included confounding, selection of participants, and missing data. (Refer to Appendix F for details of the ROB assessments.)

The intervention delivery mode varied widely among these 6 studies. Half of the studies used a virtual deployment method (2 web-based, self-directed;^32,37^ 1 online chat group^33^) and half used a group-based format.^30,33,38,54^ For those delivered in person, 1 used a home-based program^29^ and 2 studies^30,38,47,53^ focused on in-person multi-family group interventions. While none of these interventions were delivered by health care providers, 4 studies used a trained professional, which included peers, health promotion workers, graduate students, and non-licensed facilitators, to deliver the intervention. The other 2 studies^32,37,42^ were self-directed internet-based programs with no interventionists to deliver the content. One of these online programs^32^ offered access to a listserv co-moderated by a parent with mental illness and a mental health professional. For synchronous parenting skills interventions, sessions ranged in length from 30-minute-^42^ to 2-hour^33^-long sessions over the course of 8^33^ to 14^47,53^ weeks. The 2 asynchronously self-directed internet-based studies^32,37,42^ ranged from 10 weeks to 3 months (Table 5).

Table 5 Characteristics of Effective Parenting Skills Training Programs

Intervention Type | Target Population (n) | Intervention Name (Parenting Skills Training Program) | Intervention Techniques | Child Involvement | Provider Type | Dose
Study and Design | Target Population (n) | Intervention Name (Parenting Skills Training Program) | Intervention Techniques | Child Involvement | Provider Type | Dose
KQ1: Populations with Parental Histories of Military Service
In-person Multi-family Group Intervention
Gewirtz, 2018^47,53^; RCT | National Guard and Reserve Families with 1 parent who had deployed to recent conflicts (N = 336 families; 608 parents) | After Deployment, Adaptive Parenting Tools (ADAPT); (Parent Management Training Program – Oregon model)^48^ | Rehearsal, role playing, or practice, curriculum or manual | No | Trained peer/lay person facilitator, including military-connected facilitator | Fourteen weekly 2-hour sessions
KQ2: Populations with Parental Histories of Serous Mental Illness
Home-based Self-help Workbook With Facilitated Engagement
Wolfenden, 2022^29^; Repeated measures study | Schizophrenia spectrum disorder (N = 10) | Triple P (Positive Parenting Program)^39,40^ | Curriculum or manual, home-based components, homework, modeling | Observed parent-child interactions during home visits | Non-licensed trained facilitator (includes graduate students) | Ten sessions delivered weekly over 10–14 weeks, lasting 45–60 minutes
In-person Multi-family Group Intervention
Serravalle, 2021^30,38^; Controlled before-after study | Bipolar disorder (N = 55 families) | Reducing Unwanted Stress in the Home (RUSH); Parenting program: How to behave so your children will too!^55^ | Curriculum or manual, observations of parent-child interactions NOT at home | Separate, but concurrent child sessions | Non-licensed trained facilitator (includes graduate students) | Parents: 12 2-hour sessions over 12 weeks; Child sessions were 1 hour long, with 5 individualized bi-weekly booster calls that lasted 15 minutes each
Virtual Group-based Chat Intervention
van der Zanden, 2010^33^; Uncontrolled before-after design | Parents with mental illness (N = 48) | KopOpOuders, translated from Dutch: Chin Up, Parents; (No named parenting skills training program) | Curriculum or manual, homework | No | Trained health promotion workers | Eight 90-minute weekly sessions
Web-based Self-directed Intervention
Jones, 2015^37^; RCT | Bipolar Disorder (N = 78) | Triple P (Positive Parenting Program)^39,40^ | Curriculum or manual, homework | No | Electronic/non-human | Ten weeks
Kaplan, 2014^32^/O’Shea, 2019^42^; RCT | Mothers diagnosed with schizophrenia spectrum or mood disorder (N = 60) | Parenting Internet Education; (No named parenting skills training program) | Curriculum or manual, homework | No | Electronic/non-human | Three months of 30-minute weekly sessions

### Intervention Skills and Techniques

All 6 parenting skills interventions followed manualized protocols, covering pre-specified curricula. All but 1 study incorporated homework assignments to complete between sessions to reinforce parenting skills. Three of the interventions were adapted from an evidence-based parent management training model. Two studies^29,37,56^ were based on the Triple P Positive Parenting Program,^39,40^ and 1^47,53^ on the Parent Management Training-Oregon Model (PMTO).^47,48,53^ One intervention was based on a program in the lay press.^55^ Based on a coding scheme used in a CDC-sponsored systematic review^5^ of parenting components associated with parenting training program effectiveness, we mapped elements of the 6 programs to the 8 content components commonly used in parenting skills training programs. (See Appendix D for a description of these components.) Most studies focused on interventions that developed parental skills or knowledge in 4 key areas: discipline and behavior management (5 studies), positive interactions with child (5 studies), promoting children’s social skills or prosocial behavior (4 studies), and emotion communication (5 studies). Although not as broadly covered across studies, other skills that were highlighted in these studies’ interventions included child development knowledge and care, disciplinary communication, and promoting children’s cognitive or academic skills. These domains are outlined in the parenting skills and knowledge matrix (Table 6).

None of the virtual interventions included direct contact with children. Two of the 3 in-person studies directly involved the children of the parent participants.^29,30,38^ The study by Wolfenden et al^29^ incorporated an in-home visit for parent-child observations, while Serravalle et al^30,38^ incorporated parent-child observations outside of the home and 12 in-person weekly group session for children that were run concurrently with the parents-only multi-family group sessions.

Table 6 Parenting Skills and Knowledge Components Across the Effective Parenting Interventions

Study | Child Development Knowledge and Care | Positive Interactions with Child | Responsiveness, Sensitivity, and Nurturing | Emotion Communication | Disciplinary Communication | Discipline and Behavior Management | Promoting Child Social Skills or Prosocial Behavior | Promoting Child Cognitive or Academic Skills | Total Number of Components
Gewirtz, 2018^47,53^ | N | Y | Y | Y | Y | Y | N | Y | 6
Jones, 2015^37^ | N | Y | N | Y | Y | Y | Y | N | 5
Kaplan, 2014^32^ / O’Shea, 2019^42^ | Y | N | N | N | N | Y | N | Y | 3
Serravalle, 2021^30,38^ | N | Y | N | Y | Y | Y | Y | N | 5
van der Zanden, 2010^33^ | Y | Y | N | Y | N | Y | Y | N | 5
Wolfenden, 2022^29^ | Y | Y | Y | Y | N | N | Y | N | 5

### Implementation Factors

We also explored selected implementation factors related to engagement: recruitment techniques, intervention adherence, and participant satisfaction with parenting programs.

#### Recruitment Techniques

In general, recruitment techniques focused on potential participants within settings that were frequented by the population of interest, such as parent support groups, family picnics, mental health service centers, reintegration events, or health care clinics. The most common recruitment techniques included advertisements in newsletters, email, magazine postings, and websites. Other common recruitment methods included outreach to local support meetings and referrals from service providers (ie, general practitioners, social services, homecare services). One study^37,56^ with a web-based intervention emphasized online recruitment methods. For military-connected families, recruitment focused on reintegrating events for military families, through collaboration with local VA health care centers and Veteran service organizations deployment.^57^

#### Adherence to Intervention

Only 4 of the studies reported on adherence to the intervention. In the ADAPT intervention,^47,53,57^ an in-person group intervention, 75.4% of participants attended at least 1 in-person group session, and 70.7% of sessions were attended by at least 1 parent. Engagement in the intervention was enhanced when the group sessions were led by a military-connected facilitator (73.25% vs 59.78% sessions, p = 0.01). The other in-person group intervention also reported high rates of adherence to the intervention. In a proof-of-concept study of a multi-family group for parents with bipolar disorder and their children, 76% of families completed the 12-week program.^30,38^ In contrast, an online chat group intervention reported low levels of intervention engagement as measured by website usage and completed sessions.^33^ In total, 57% of participants completed at least half of the sessions and only 20% attended all 8 weekly sessions. The remaining intervention was a home-based parenting program with home visits assessed in a small, repeated measures study^29^ of 10 parents with psychosis. In sum, 50% of the parents with psychosis completed all 10 weekly sessions.

#### Participant Satisfaction

Three studies^29,33,54,57^ reported participant satisfaction with the intervention. Overall, parent satisfaction with parenting skills training interventions was very high. In the ADAPT multi-family group intervention among military families,^54,57^ participants reported high satisfaction with group sessions (mean = 3.44, SD = 0.48; range: 0 to 4). The online group chat intervention^33^ also reported high program satisfaction (mean = 7.8; SD = NR, range: 1–10). The final study^29^ assessed participant satisfaction both quantitatively and qualitatively with a home-based program. Qualitative findings were overwhelmingly positive, though participants noted literacy issues with the self-help materials. Quantitative^29^ evaluations were also favorable. Parents rated overall satisfaction with the program very high with an average score of 95% (range of participant scores: 76%–100%).