# METHODS

## TOPIC DEVELOPMENT

This topic was requested by the VHA Office of Mental Health and Suicide Prevention. The key questions and eligibility criteria were informed through feedback from VA operational partners and a technical expert panel assembled for this review.

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 Among parents with a history of sexual trauma, what are the effects of parenting skills training interventions on key parent, family, and child outcomes?
KQ2 Among parents with a history of serious mental illness, what are the effects of parenting skills training interventions on key parent, family, and child outcomes?
KQ3 Among parents with a history of military service, what are the effects of parenting skills training interventions on key parent, family, and child outcomes?
KQ4 What are intervention characteristics (eg, format, dose, content) of the identified effective parenting skills training interventions?

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022383964).

## DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, a research librarian searched MEDLINE (via Ovid), Embase (via Elsevier), APA PsycINFO (via Ovid), and CINAHL (via EBSCO) Complete from inception to September 2022 using a combination of database-specific controlled vocabulary terms and keywords searched in the titles and abstracts related to parenting skills, military, Veterans, sexual trauma, and mental illness (see Appendix A for complete search strategies). An experienced medical librarian devised and conducted the search with input on keywords from the other authors. The search strategies were peer reviewed by another librarian using a modified PRESS checklist.^27^ Case reports, editorials, letters, comments, and conference abstracts were excluded from the search, as were animal-only studies. Study selection was based on the eligibility criteria described below. Given the lack of studies identified for KQ1, we screened ClinicalTrials.gov for any studies underway that describe interventions for parents with a history of sexual trauma in adulthood.

## STUDY SELECTION

### Eligibility Criteria

Studies identified through our primary search were classified independently based on title and abstract by 2 investigators assessing relevance to the KQs from our a priori established eligibility criteria (Table 1). All citations classified for inclusion by at least 2 investigators were reviewed at the full-text review level. Two investigators agreed on exclusion at title and abstract as well as full-text review levels. We tracked screening in electronic databases (for referencing, EndNote; PICO Portal for screening and data extraction).

Table 1 PICOTS Eligibility Criteria

Study Characteristic | Inclusion Criteria | Exclusion Criteria
Population^a^ | Community-dwelling biological, adoptive, or parent figures/guardian (eg, grandparents as primary caregivers) aged 18 and over of children aged 2 to 17 with histories of:; KQ1: Sexual trauma in adulthood (eg, military sexual trauma); KQ2: Serious mental illness (SMI) as determined by meeting 1 of the following criteria:; - The population under study has at least 1 of the following conditions: schizophrenia or other psychotic disorder; bipolar disorder; major depressive disorder (MDD); posttraumatic stress disorder (PTSD) or borderline personality disorder (BPD); - The population under study is explicitly labeled as SMI by the study authors even if the operationalized definition of SMI is different (could also be labeled as severe and persistent mental illness or SPMI); KQ3: Military service in the United States or other countries’ armed forces, including those now separated from service (ie, Veterans); KQ1-3: Any mixed populations comprised of conditions/exposures listed for KQ1-3 if meeting 75% or more of the overall study population | - Family caregivers who are not primary caregivers; - Parents of infants and children under age 2; - Mixed populations of infants and children if the children under age 2 comprise 25% or more of the total population; - Inpatient populations; - Imprisoned populations
Intervention | Manualized/protocolized parenting skills training interventions that are appropriate for parent figures of any gender identity that are intended to prevent adverse child and family outcomes (eg, aggressive behaviors) or increase parenting capacity (eg, increasing use of effective discipline; promoting nurturing behaviors to support positive parent-child interactions; responding sensitively to child’s emotional needs). A parenting skills training program must include modeling, homework, rehearsal/role play, or practice that promotes the acquisition of parenting skills; Parenting skills programs may include enhancements (eg, additional psychoeducation) that aim to address needs of specific parent groups (eg, SPMI, sexual trauma, military service); Qualifying programs can be delivered:; - Virtually or in-person; - Individually or in groups; - Synchronously (video, telephone) or asynchronously (eg, self-paced video tutorials on a website) | - Parenting interventions where eligibility for the study and program are based on a child’s qualifying condition (eg, children with physical, learning, or developmental disabilities, or with mental health conditions); - Peer or professional led support groups without manualized content; - Multi-modal programs that include individualized or group adjunctive psychotherapies (eg, cognitive behavioral therapy, dialectics behavioral therapy) aimed at improving the mental health condition of the parent without parenting skills training components
Comparators^b^ | Any comparator (eg, usual care, active comparator, historical controls) | No comparator
Outcome^b^ | KQ1-3:; - Parent outcomes (ie, emotion regulation, positive parenting skills, parenting knowledge, parenting self-efficacy, parental stress); - Family outcomes (ie, family conflict, family functioning); - Child outcomes (ie, disruptive behaviors); KQ4: Characteristics of effective parenting programs such as:; - Content (eg, use of home-based components or visitations, homework or practice between sessions, observations of parent-child interactions); - Format (eg, group-based, virtual, involvement of child in parenting program); - Dose; - Recruitment technique, enrollment, engagement or adherence, or; - Implementation factors (eg, barriers or facilitators to implementation, qualifications of the interventionist, satisfaction with training program) | Any outcomes not listed
Setting | - Community or outpatient setting; - Virtual or in-person setting | - Inpatient care; - Residential programs; - Prison
Study design | - Randomized trials; - Nonrandomized trials; - Controlled before-after studies; - Interrupted time-series studies or repeated measures studies; - Prospective and retrospective cohort studies; - Uncontrolled before-after studies (ie, pre-post study). | - Descriptive studies with no outcomes data; - Qualitative studies; - Case reports and case studies with no outcome information; - Studies that included only outcomes data from 1 point in time (post only, uncontrolled clinical study); - Modeling studies that used simulated data; - Not a clinical study (eg, editorial, nonsystematic review, letter to the editor); May also exclude if there are many studies:; - Self-described pilot studies without adequate power to assess impact of intervention on outcomes.; - Studies of small sample sizes (N < 100)
Countries | OECD^c^ | Non-OECD
Publication types | Full publication in a peer-reviewed journal | - Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results; - Publications in predatory journals^d^ (eg, rapid pay-to-publish models without rigorous peer review)

Notes.

a For the population of interest, we took a first-order approach and only retained (1) studies conducted with the populations of interest or (2) studies that present subgroup analysis, or moderator analysis, by populations of interest.

b Primary studies had be comparative in design. Yet outcomes for KQ4 did not need to be comparative (eg, satisfaction with intervention, barriers, facilitators).

c OECD 2022=Organization for Economic Co-operation and Development includes Australia, Austria, Belgium, Canada, Chile, Colombia, Costa Rica, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Lithuania, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States.

d There is no single way to identify all the predatory journals, as this is a rapidly evolving industry. Thus, we will use the best available guidance to scrutinize potential problematic studies such as pay-to-publish models, lack of rigorous peer review, rapid publishing timelines, lack of impact factor information, and being identified as a potential problematic journal by the field, and expert librarian consultation.

## DATA ABSTRACTION AND ASSESSMENT

Data from published reports were abstracted into PICO Portal by 1 reviewer and over-read by a second reviewer. We resolved disagreements by consensus or by obtaining a third reviewer’s opinion when consensus could not be reached between the first and second reviewers. Key information abstracted included participant descriptors (eg, age, sex, race, diagnosis; see Appendix C), intervention characteristics (eg, parenting program, parenting skills techniques, theoretical foundation, dose; see Appendix D), comparator, and outcomes. Multiple reports from a single study were treated as a single data point, prioritizing results based on the most complete and appropriately analyzed data. When critical data were missing or unclear in published reports, we requested supplemental data from the study authors. Key features relevant to applicability included a match between the sample and target populations (eg, age, comorbidities, Veteran status).

## SYNTHESIS

We summarized the primary literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention and comparator. To aid interpretation of results, we synthesize the results for each category of outcome (ie, parent-level, family-level, child-level) by intervention type (eg, in-person multi-family groups, web-based self-directed modules). Outcomes were grouped by consensus among a small group of investigators with content expertise (ND, JS, JMG, AMG) using face validity and external resources. We grouped outcomes into similar intervention types. Interventions were also grouped by consensus (JMG, AMG). (Appendix E has a brief description of the content of the parenting skills intervention programs.)

We conducted quantitative synthesis (ie, meta-analysis) when there were at least 3 studies with the same outcome, based on the rationale that 1 or 2 studies do not provide adequate evidence for summary effects. For meta-analyses, feasibility depends on the volume of relevant literature, conceptual homogeneity of the studies, and completeness of results reporting. When quantitative synthesis was possible, continuous outcomes were synthesized as standardized mean differences (SMD). We evaluated statistical heterogeneity using visual inspection and 95% prediction intervals using the metafor^28^ package for R (R Foundation for Statistical Computing, Vienna, Austria). When a quantitative synthesis was not feasible, we narratively analyzed the data. We gave more weight to the evidence from higher quality studies with more precise estimates of effect. Our approach to narrative synthesis focused on identifying patterns in intervention effects. We then explored potential reasons for inconsistency in treatment effects across studies by evaluating underlying differences in the study populations, interventions, comparators, and outcome definitions.

### Analysis of Subgroups or Subsets

When meta-analyses were feasible, we considered subgroup analysis or meta-regression to explore quantitative or qualitative interactions of prespecified potential effect modifiers such as study design (eg, allocation concealment) and, potentially, intervention approach. For patient-level characteristics of interest (ie, sex, race/ethnicity, age), we identified analyses conducted within the primary literature that evaluated effect modification (eg, subgroup analyses, regression model explanatory variables). When we were unable to conduct meaningful quantitative analysis of effect modification across characteristics of interest, we narratively considered the representation of subgroups within identified studies in comparison to the VA population.

### Grading the Certainty of Evidence

The certainty of evidence (COE) for each key question was assessed using the approach described by the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group.^28^ We limited GRADE ratings to those outcomes identified by the stakeholders and technical expert panel as critical to decision-making (ie, parenting skills, parenting self-efficacy, parental stress, emotion regulation of parent, family functioning/conflict). In brief, the GRADE approach requires assessment of 4 domains:

- Risk of bias (eg, Are there major limitations in included study designs for this outcome?)
- Consistency of effects (eg, Do point estimates vary widely across studies on this outcome?)
- Directness (eg, Are we confident the evidence directly compares interventions of most interest to key stakeholders? Are these interventions assessed in populations of interest to key stakeholders?)
- Precision (eg, For this outcome, are there relatively few patients? Are the 95% confidence intervals wide?)

Additional domains to be used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and we assigned a summary COE rating after discussion by 2 investigators (AMG, JMG). For each KQ, we conducted our COE assessments by intervention type (eg, in-person group) for each outcome. In keeping with GRADE guidelines, we also provide separate COE ratings for randomized studies and observational studies.