# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) is responding to a request from the VHA Office of Mental Health and Suicide Prevention for a systematic review of the effectiveness of parenting skills training programs on key parent, family, and child outcomes, and the implementation considerations for effective parenting programs. Findings from this review will be used to inform national policy recommendations in a congressionally mandated report.

## BACKGROUND

Evidence-based parenting programs have demonstrated effectiveness for increasing parenting confidence, minimizing family stress, and improving parent-child relationships.^1,2^ These programs typically include core components, such as direct teaching of specific positive parenting skills (eg, active listening, reducing negative communications, engaging in child-selected play) and explicit instructions to practice skills.^3–6^ Yet the majority of evidence-based behavioral parenting programs have centered on the child’s presentation, including behavioral or emotional challenges,^7^ rather than on the characteristics of parents. It is unclear whether these parenting interventions centered on children’s characteristics (eg, autism spectrum disorder, attention deficit and hyperactivity disorder) would be effective for parents with unique needs and experiences including histories of sexual trauma, serious mental illness, and/or military service. Studies suggest that different types of parental stress can impact parenting behaviors in distinctive ways.^8^

While parenting can be challenging for any person, parents who have experienced significant stress from their own traumatic exposures or health conditions may face even greater obstacles in their family systems.^9–12^ Such excess parental stress can have immediate negative consequences on family functioning and lasting influence on the child and family, including, but not limited to, mental health issues, behavioral problems, substance use, child maltreatment, and increased healthcare utilization.^12^ Among Veterans, an important source of excess family stress is a parental history of sexual trauma, including military sexual trauma.^13^ Differences in parenting practices have been observed in both civilian and Veteran populations among women with sexual trauma.^8^ For example, mothers with histories of sexual trauma can have impaired interactions with their infants^14^ and be less sensitive and more intrusive with school-age children.^15^ Serious mental illness also has been found to be a risk factor for negative parenting practices and family dysfunction. For example, parents with a history of posttraumatic stress disorder (PTSD) are more likely to have higher levels of parenting stress, impaired family functioning, and more frequent use of negative parenting practices.^16,17^ Similarly, parents with depression report lower levels of parenting self-efficacy, which can worsen parental depression and positive parenting practices.^18^

Military Veterans are at high risk for experiencing stressors that can impact parenting practices.^14,19,20^ Prolonged separations from the family, deployments to stressful environments, and exposure to potentially traumatic events are common experiences for military personnel. Also, military Veterans are at higher risk for serious mental illness,^21,22^ a known contributor to parenting challenges.^20^ While not all military-connected families will experience negative family sequala due to their experiences in military service, previous research has shown that parental military service can be a family stressor associated with parenting difficulties and impaired family functioning.^23,24^ Providing interventions to enhance parenting practices and support parents who have experienced, or are at high risk for experiencing, excess family stress can be a critical tool for improving family functioning.^25^ Moreover, there is evidence that parental mental health may not impede the benefits of parenting skills training programs.^26^

The Veterans Health Administration (VHA) is the country’s largest integrated health system and as such has a mandate to care for Veterans across the entire United States and associated territories. Given that military Veterans are more likely to experience mental health and trauma stressors, the Veteran population served by the VHA may benefit from parenting skills training programs. Yet it is unknown if parenting programs are effective among populations that have family stressors like those of the Veteran population. The VHA has piloted Parenting Skills Training in Affective and Interpersonal Regulation (Parenting STAIR), a program for which there are no published evaluations among Veterans. The current systematic review aimed to (1) understand whether, and in what ways, parenting skills training programs can effectively support parents who are at increased risk for stress due to parental history of sexual trauma in adulthood and/or serious mental illness, as well as parents with histories of military service, and (2) clarify characteristics of effective parenting skills training programs.