# APPENDIX G PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
5 | 5 | Yes | Thank you.
6 | 6 | Yes | Thank you.
7 | 7 | Yes | Thank you.
8 | 8 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
9 | 1 | No | Acknowledged; thank you.
10 | 2 | No | Acknowledged; thank you.
11 | 3 | No | Acknowledged; thank you.
12 | 4 | No | Acknowledged. Thank you.
13 | 5 | No | Acknowledged. Thank you.
14 | 6 | No | Acknowledged. Thank you.
15 | 7 | No | Acknowledged; thank you.
16 | 8 | No | Acknowledged; thank you.
Are there any published or unpublished studies that we may have overlooked?
17 | 1 | Yes - Please consider adding the following to discussion section: There has been one published study of Parenting STAIR. It is a pre-post, open trial, but has direct relevance to this review and legislation we are responding to. https://link.springer.com/article/10.1007/s10826-023-02534-y | Thank you for this comment. Please note that the article mentioned here was indexed in Medline after our search. Yet, we did cite and comment on this article in the Discussion section of the report. To address this comment, we have added some additional contextual information in the Discussion section, including how the published uncontrolled before and after study of Parenting STAIR differs from the Parenting STAIR piloted in the VA.
18 | 1 | There is a small literature on preventative interventions for expecting parents with histories of trauma/sexual trauma that may have relevance and has been recently summarized in a review. https://pubmed.ncbi.nlm.nih.gov/29558671/. See also https://www.growingforwardtogether.org/ | The review cited here is centered on expectant parents who have histories of child sexual trauma. In consultation with our VA operational partners and the Technical Expert Panel, the key question related to trauma focuses on military sexual trauma and the civilian equivalent of sexual trauma in adulthood. Also the review suggested here is about expectant parents. Our review is focused on parents of children aged 2 to 17. Thus, the suggested review seems to be out of the scope of this current systematic review centered on parents with conditions common among Veterans.
19 | 2 | No | Acknowledged. Thank you.
20 | 3 | No | Acknowledged. Thank you.
21 | 4 | No | Acknowledged. Thank you.
22 | 5 | Yes - Page 6, line 45. “While we did not identify any studies conducted only among parents with PTSD”.; I’m not seeing the articles below on the included reference lists. While I believe they would both be excluded due to the study selection criteria described earlier in the paper, I did not find them on the list of excluded articles either.; Casselman, R. B., & Pemberton, J. R. (2015). ACT-Based Parenting Group for Veterans with PTSD: Development and Preliminary Outcomes. The American Journal of Family Therapy, 43, 57–66.; Creech . (2022). Pilot Trial of Strength at Home Parents: A Trauma-Informed Parenting Support Treatment for Veterans. Couple and Family Psychology: Research and Practice, 11, 205–216.36185500 | Thank you for highlighting these studies. You are correct that our search did not discover these 2 studies.; In reference to Casselman (2015): Upon review of our search approach, we note that this journal (and, as a result, this paper) is not indexed in two of the primary databases we searched (MEDLINE and Embase). The journal is indexed in the other two databases we searched – both APA PsycINFO and CINAHL Complete. We believe the article would have shown up among those results. However, we regret that we did not include the keyword “psychoeducation” in our keyword search strategy of titles and abstracts, as the use of that term would have retrieved this particular paper. In reviewing this paper, we have determined it is not eligible for this review. This paper, which has pre-post outcome data for 3 Veterans does not report on any outcomes of interest.; The article by Creech et al 2022 was published after we executed our search. Thus, we did not have this study in our tables. We have highlighted this study in our Discussion in a section called “Recent Studies and Ongoing Work.”
23 | 6 | No | Acknowledged; thank you.
24 | 7 | No | Acknowledged; thank you.
25 | 8 | No | Acknowledged; thank you.
Additional suggestions or comments can be provided below.
26 | 1 | Thank you for the extended time to review this draft and report. Overall, this is well done and we appreciate efforts to complete this work on schedule!; The numbering and ordering of key questions is not consistent. We prefer that KQs be consistently listed in order of relevance to the legislation…and consistent with the topic nomination: KQ1 = parenting history of sexual trauma, KQ2 = parenting diagnosis of SMI, KQ3 = parent history of military service, KQ4 = intervention characteristics. | Thank you. We have reordered the key questions.
27 | 1 | Please add abbreviations table. | We add an abbreviations table to all final reports. This table has been added to this final report.
28 | 1 | The introduction and future directions sections suggest that military service alone is a risk factor for parenting problems. I think it is more accurate (and may make more sense to the reader) if the rationale for this review is framed around an interest in parent characteristics (particularly history of trauma/SMI in Veterans) that may affect parenting, as opposed to helping parents to manage children with behavioral problems (i.e., focus on parent characteristics vs child characteristics). | Thank you for this comment. The Introduction and Discussion sections have been revised to reflect the focus of this systematic review is on parental stressors common among Veterans.
29 | 1 | Parenting STAIR is not a VA-wide program. Please correct throughout. | Acknowledged
30 | 1 | Please omit several specific inferences and recommendations about national VHA policy that I think are beyond the scope of this review, which I’ve noted in comments. | We did not intend for this review to be interpreted as making recommendations about national VHA policy. We have revised these selected instances to improve clarity and focus.
31 | 1 | The report title strikes me as a bit clunky and I don’t know that “family stressors related to military service” captures our primary focus. | We have revised the title of the report.
32 | 1 | Why use history of sexual assault (rather than history of sexual trauma) as the language of KQ? | In consultation with the technical expert panel assembled for this review, we refined the scope to encompass the civilian equivalent of military sexual trauma, sexual trauma in adulthood, to better align with the original rationale for this systematic review. Sexual assault was the language used in the key questions but our search was inclusive of sexual trauma. We have revised the language to improve clarity throughout the report that the parental exposure is sexual trauma in adulthood.
33 | 1 | [Executive summary second paragraph of introduction] The order in which risk factors are described is a bit confusing. First paragraph in this section is about trauma and second paragraph mentions military history and then SMI (almost as if they were reviewed together, rather than separately), and then military history is discussed again in 3rd paragraph. | We appreciate the reviewer’s comments and have revised the Executive Summary and Introduction for clarity.
34 | 1 | [Executive summary second paragraph of introduction] Before switching focus from trauma to SMI, consider adding a brief summary of the potential impact of parent history of sexual trauma in particular (rather than trauma in general). That would round out a description of the rationale for why this report was requested – why nominating partners (and others) do not think more general parenting skills training may not be well-suited to meet the needs of Veterans who have experienced sexual trauma.; For reference/context, this is the language of the legislative requirement:; …conduct a study on the feasibility and advisability of expanding the Parenting STAIR program to all medical centers of the Department of Veterans Affairs and including such program as part of care for military sexual trauma for affected members and former members of the Armed Forces.; Parenting STAIR is an intervention that was developed for adult survivors of military sexual trauma who are experiencing parenting difficulties related to their sexual trauma history. | Thank you and we have revised the Introduction section and its corresponding elements in the Executive Summary.
35 | 1 | [Executive summary last paragraph of introduction] Ditto here about order in which these are listed – would prefer that they are listed in same order consistently, and that ordering align with order of interest. | We have rewritten this paragraph and reordered the topics so they align with the KQs.
36 | 1 | [Executive summary first paragraph of discussion] I believe we shared one in-press manuscript with the team. | This comment is in reference to the recently published article Sullivan, K.S., Ancharski, K., Wortham, W. . Feasibility and Preliminary Impact of a Community-Based Intervention for Maternal PTSD and Parenting: Parenting-STAIR Pilot. J Child Fam Stud 32, 481–497 (2023)36685737 . This article was indexed in Medline after our search. Yet, we did cite and comment on this article in the Discussion section in the draft report. To address this comment, we have added some additional contextual information on this study in the Discussion section and note that there are no published studies of Parenting STAIR among Veterans.
37 | 1 | [Executive summary first paragraph of discussion] It may also be worth clarifying that the focus here is on parenting problems that stem from parent characteristics/experiences rather than child characteristics. I think that’s a useful distinction that helps to frame this review. | We agree this is a useful distinction and have incorporated this change into the Executive Summary, introduction, and Discussion.
38 | 1 | [Executive summary second paragraph of discussion] As our focus is on parenting skills training interventions that are designed for and/or have been tested in our populations of interest (and KQs are framed in terms of parent characteristics), I suggest that this section be organized to match KQs, including a brief discussion of key findings/strength of evidence related to parent characteristics (military service/Veterans, history of trauma/sexual trauma, SMI; i.e., KQ1-3) before description of characteristics of effective programs (KQ4) | We have revised the Discussion section and parallel content in the Executive Summary.
39 | 1 | [Executive summary last sentence of the key findings and strength of evidence section] It’s not clear to me which rates are referred to here. | We have revised this section to improve clarity.
40 | 1 | [Executive summary future research section] Given focus of this report, perhaps future research should not explore interventions that are designed to address parenting problems associated with military service/deployment and trauma exposure. In other words, it’s not so much the parent population (Veteran/military versus civilian) but developing and testing interventions that are designed to address the specific types of parenting problems experienced by our population of interest. | We appreciate the reviewer’s attention to a core consideration for this work. There are diverse factors that impact parenting and people’s experience as parents. Given that military service can shape individuals and families in multiple ways (eg, extended deployments that impact family dynamics and patterns, increased risks of exposure to traumas, exposure to different cultures, separation from extended family), it seems likely that interventions for Veteran parents and families should take these experiences and exposures into consideration. Future research could address programmatic adaptations such as timing and frequency of sessions, involvement of other parental caregivers, and opportunities for peer support, which may be relevant for improving outcomes for the populations of interest in this review.
41 | 1 | [Background second paragraph] Parenting problems associated with trauma history, particularly sexual trauma, was intended to be the primary focus of this review. Suggest adding a brief paragraph about potential impacts of sexual trauma on parenting | We have revised the background section in light of this comment to highlight the parenting experiences that are framing the rationale for the review.
42 | 1 | [Background fourth paragraph] Would it be accurate to say that most evidence-based parenting programs are designed to address parenting problems linked with child characteristics as opposed to parent characteristics? | Yes, most evidence-based parenting programs (eg, PCIT, Triple P, Defiant Child) have focused on child characteristics rather than parent characteristics. We have added a note about this to the Executive Summary and Introduction.
43 | 1 | [Background last paragraph] The logic here and link to the impetus for this ESP nomination doesn’t follow for me. | We have significantly revised the Background section.
44 | 1 | [Background last paragraph] I’m not sure it’s necessary to repeatedly mention the due date for our report. If you want to include due date, it is due to our leadership in November. The finalized and fully cleared report is due to Congress in early January 2024. | Acknowledged
45 | 1 | [Table 1] Military sexual trauma is defined by VA as sexual assault or sexual harassment experienced during military service. This is why I have suggested in various places in report that we replace ‘sexual assault’ with ‘sexual trauma’, to align with definition of MST. | We have revised the wording throughout to align with the concept of “military sexual trauma.” Our search was sufficiently broad to detect the phenomena of sexual trauma.
46 | 1 | [Table 1] Should be emotion regulation throughout | Acknowledged
47 | 1 | [Discussion first paragraph in reference to “currently implementing”] Not accurate | Acknowledged
48 | 1 | [Discussion first paragraph] Published January 2023: Sullivan, K.S., Ancharski, K., Wortham, W. . Feasibility and Preliminary Impact of a Community-Based Intervention for Maternal PTSD and Parenting: Parenting-STAIR Pilot. J Child Fam Stud 32, 481–497 (2023). 10.1007/s10826-023-02534-y 36685737 | Thank you. Please see response above about this study.
49 | 1 | [Discussion third paragraph of the key findings and certainty of evidence: parents with a history of mental illness] There is not a VA STAIR parenting program. Parenting STAIR is a treatment that was piloted in VA. Rather than try to make that distinction, consider instead noting that ratings were downgraded if the assessed intervention did not align with elements operational partners indicated would enhance feasibility of VA implementation (for instance, a home based intervention is not easily implemented within VA, nor is one involving children or chat-based). | Thank you for this clarification. The Discussion section has been revised.
50 | 1 | [Discussion third paragraph of the key findings and certainty of evidence: parents with a history of mental illness] I disagree. The goal was to identify all parenting interventions appropriate for our patient population and for implementation by VA. A web-based format is feasible to be implemented in VA. It does not make sense to downgrade based on similarity/difference from Parenting STAIR which is not evidence-based and has not been nationally implemented in VA. | Thank you. We have clarified how we are operationalizing indirectness for GRADE in the Methods and Discussion sections.
51 | 1 | [Clinical and policy implications first paragraph] We are not prioritizing young children over others under age 18. The majority of male and female Veterans are too old to have young children at home. | We appreciate the reviewer’s comment about our description of young children, and we have removed this statement.
52 | 1 | [Clinical and policy implications second paragraph] Suggest omitting this statement as comments about national VA policy is outside the scope of this review. | We appreciate the reviewer’s comment about our mention of a VHA service which includes integration of spouse caregivers. Although we acknowledge that the particular program we noted is designed to broaden caregiving capacity directly for the Veteran, the program is relevant to our current report. Specifically, parenting programs similarly offer support directed toward the Veteran by addressing family stress. We have modified the text to reflect this perspective.
53 | 1 | [Clinical and policy implications third paragraph in reference to parents who attend with their children] I don’t think current evidence is sufficient to support this statement and this is a very broadly stated conclusion that is beyond the scope of this review. I think this remains an empirical questions. | We appreciate the reviewer’s comment that there are outstanding questions about the extent to which parental attendance, engagement, and practice are tied to outcomes of parenting programs. However, research supports the idea that parents need to interact with the program material in order to gain benefit from it. We have added references to the text to support this statement.
54 | 1 | [Clinical and policy implications third paragraph] These stressor sound more relevant to post-deployment families (many still military) rather than Veterans. | Given that military service can shape individuals and families in multiple ways (eg, extended deployments that impact family dynamics and patterns, increased risks of exposure to traumas, exposure to different cultures, separation from extended family), it seems likely that interventions for Veteran parents and families should take these experiences and exposures into consideration.
55 | | [Clinical and policy implications third paragraph in reference to access and flexibility] Isn’t this also largely an empirical question?; I don’t think we know enough about the comparative efficacy of telehealth vs face-to-face parenting skills training, or important implementation factors such as adherence and retention. | We thank the reviewer for noting that research on telehealth parenting interventions is still growing. However, there is emerging evidence that these interventions are effective, and some studies have shown no differences from face-to-face treatment.; We have included some additional references to address these questions.
56 | 1 | [Clinical and policy implications third paragraph regarding internet connection] Which may not be available in all areas of the country, such as highly rural. | Thank you. We mention this in the report
57 | 1 | [Clinical and policy implications fourth paragraph] Not clear which populations are referred to here. | We apologize for the lack of clarity in this statement, and we have edited the text accordingly:
58 | 1 | [Clinical and policy implications fourth paragraph] In what way does type of provider (licensed clinician or peer specialist) affect adherence? I’m not following. | We have revised this sentence for clarity.
59 | 1 | [Clinical and policy implications fourth paragraph] I believe authors are referring to peer specialists, who are employed by VA and trained to use their lived experience of mental health recovery to help patients with mental health concerns (peer specialists’ scope is limited to mental health settings). | Yes, the reviewer is correct and we have made this distinction clearer in the report.
60 | 1 | [Clinical and policy implications fourth paragraph] I don’t see this (lack of service availability in the community) as primary drawback (of community care). I see disconnect between Veterans VHA care and community care, cost to VA and fit with Veterans’ specific parenting problems as key drawbacks. | We appreciate the reviewer’s comments that there are multiple potential drawbacks to community care, apart from limited availability of parenting programs more generally. We modified the text to include additional suggestions made by the reviewer.
61 | 1 | [Prior systematic reviews first paragraph] It may also be worth mentioning prior reviews in expecting/new parents with trauma histories, such as: https://pubmed.ncbi.nlm.nih.gov/29558671/; [Discussion ongoing work section] Another option VHA may want to consider is prevention oriented approaches that target at risk populations. For example, an intervention called Survivor Mom Companion has been tested in open trials in pregnant women/new mothers with trauma histories. One could argue that it may be easier to retain women in care while they are pregnant versus after giving birth, when childcare needs may present a barrier. Julia Seng and Mickey Sperlich PIs of this work. Here’s a link to more information: https://www.growingforwardtogether.org/ | We thank the reviewer for providing information about this important intervention, which could set the stage for positive parental well-being and strong infant-parent attachment, which may reduce the chance of intergenerational transmission of trauma in the population mentioned. Although early intervention and supporting parents and young children during critical stages of development may indeed offset later challenges, the scope of the current report included parenting challenges that are relevant for children ages 2 and older. Including information on pregnancy is beyond the scope of the current report, but we agree that generally increasing support for VHA families, including during the pregnancy and immediate post-partum period, is essential.
62 | 1 | [Discussion ongoing work section] Parenting STAIR (not VA Parenting STAIR program); Do authors think this study merits more discussion? If study has been published in 2022 instead of January 2023 it would have been included in the review. Parenting STAIR is specifically named in legislation this report responds to and all subjects were diagnosed with PTSD; approx. 1/3 related to sexual trauma. | Thank you. This study has been highlighted in the recent studies section of the report, including how it is substantially different from Parenting STAIR piloted in the VA and named in the legislation.
63 | 3 | The report is well done in many respects but seems overly positive given the limited availability of quality RCTs to inform decision-making. The most valid data do not permit much by way of inferences, so I think the conclusions should be tempered to match the statistically significant evidence from moderate or low ROB trials only. | Thank you for this comment. In collaboration with our VA operational partners, we included a wide range of studies to explore the impact of parenting programs centered on parental characteristic or exposures. The GRADE process takes into account study designs and their risk of bias features. Thus, the certainty of evidence (COE) ratings capture your concerns about study design quality in rating that were generally low. We have included the COE ratings in our conclusion statement to further center findings in light of lower COE.
64 | 3 | [Key findings] It is confusing to see the inclusion of SMI families when the report is focused on military stressors. I am sure readers will understand the content better as they read on, but this initial statement suggests that the report has a broader scope than one would expect based on the title | Thank you. We have revised the title.
65 | 3 | [Methods section of executive summary] Given the interest in sexual assault, it would have been helpful to look at PTSDpubs on ptsd.va.gov | Thank you for this suggestion. We conducted a scan of this database and only found one potentially relevant study our search strategy did not identify. Upon further scrutiny of the full text, this article was also found to be an exclude.
66 | 3 | [KQ4 section of executive summary] I suggest focusing this question on RCTs only | Thank you for this comment. In collaboration with our VA operational partners, we included a wide range of studies to explore the impact of parenting programs centered on parental characteristic or exposures
67 | 5 | 1) Page 2, line 50. Inclusion of the parenting outcome of ‘emotional regulation’ is important as this would likely be a key component of a parenting skills training intervention for Veteran parents seeking care at VA. | We agree, and eligible studies needed to have at least one of the parent, family, or child focused outcomes listed in the Methods section.
68 | 5 | 2) Page 4, line 20. “The 3 studies assessed family functioning”: This wording seems a bit awkward. Perhaps, “Among the 3 studies that assessed family functioning, no studies assessed family conflict”? | Thank you for this suggested wording.
69 | 5 | 3) Page 6, line 45. “While we did not identify any studies conducted only among parents with PTSD”. I’m not seeing the articles below on the included reference lists. While I believe they would both be excluded due to the study selection criteria described earlier in the paper, I did not find them on the list of excluded articles either.; Casselman, R. B., & Pemberton, J. R. (2015). ACT-Based Parenting Group for Veterans with PTSD: Development and Preliminary Outcomes. The American Journal of Family Therapy, 43, 57–66.; Creech . (2022). Pilot Trial of Strength at Home Parents: A Trauma-Informed Parenting Support Treatment for Veterans. Couple and Family Psychology: Research and Practice, 11, 205–216.36185500 | Thank you for bringing these articles to our attention. The Creech (2022) article was published after we completed our search of the literature. Yet, we do discuss this study in the discussion section where were contextualize recent publication.; The Casselman (2015) study did not meet eligibility criteria as it did not report any outcomes of interest.
70 | 5 | 4) Page 6, line 58. “This review identified only one study conducted among Veterans”. I think this sentence could benefit by including ‘conducted exclusively among Veterans’. On page 1, line 8, “This review identified 14 unique studies: 5 among military-connected families”. Certainly, differentiating between Veteran and military-connected populations is a very valid and relevant point particularly for this systemic review. But it wasn’t until page 20, line 21 that “Only 1 study was conducted exclusively with Veterans” was mentioned so additional clarification at the beginning might be helpful for the reader.; Also of note, this distinction between parenting interventions for an exclusively Veteran population and an active-duty population is important. Many Veterans receiving VA care have separated from the military years if not decades ago and many families may have formed after the Veteran’s time in the military. Therefore, parenting content with an emphasis on deployments and returns may be less applicable to the broader Veteran population served by the VA. | Thank you. We have made these changes in the text.
71 | 5 | 5) When evaluating these parenting programs, it is also important to consider the feasibility and scalability of implementation across the VA. Parenting interventions, particularly those that involve children, can be challenging to implement in a VA setting due to logistical and administrative difficulties as well as legislative mandates that guide delivery of services and limit the scope of options for treating family members. Additionally, VA facilities are not always designed in a manner to engage family members and children.; There are also challenges with ensuring workforce capacity to address the needs of children and families. Mental health providers within the VA are focused on their primary task of treating adult Veterans as mandated by Congress. Therefore, they may not be trained or feel competent in treating families and children.; Families also face several barriers such as difficulties with scheduling and lack of childcare and may struggle to engage in lengthy, in-person interventions (page 60, line 39-48). Thus, in considering the parenting programs under discussion relevant questions also include: Who will deliver the intervention? Are VA facilities equipped to provide these interventions (e.g., appropriate spaces for families and children; ‘bug in ear’ equipment)? How long is the protocol? How will providers obtain referrals for the program? What are barriers to engagement for families and how can VA attempt to mitigate these barriers? | Thank you for these thoughtful comments. We have integrated many of these ideas into the revised Discussion section.
72 | 5 | 6) Page 22, lines 24 & 51. Interesting to note in both studies (Gewirtz et al., 2018 and Mogil et al. 2021), the majority of families had two parents participating in the program which may differentiate these samples from those in other studies. | We agree and highlight in the Executive Summary that most of the effective programs involved a family systems approach and included a spouse or child.
73 | 5 | 7) Page 29, lines 57-60. Interesting finding that participants experienced difficulty implementing the self-guided workbook and understanding tasks in this particular study. At minimum, a coach or other facilitator may be required for participants to engage, understand, and complete the protocol. | We appreciate the reviewer’s observation and have added additional text to the discussion.
74 | 5 | 8) Page 36, line 48. “Of note, use of a military-connected facilitator led to greater program participation”. This is an interesting finding from one study and potentially relevant to the questions of who will deliver the training protocol and how to increase engagement of participants. | Thank you and we agree. We have highlighted this program.
75 | 5 | 9) Page 60, line 45. Another potential benefit of group-based parenting interventions is that they may offer participating parents a network of support and information. | Thank you. We have added this contribution to the Discussion section.
76 | 5 | 10) It wasn’t clear if any of the included studies measured and reported fidelity to the protocol. Was this evaluated with the ROB domain, ‘deviations of intended interventions’? | Fidelity to the protocol is a consideration in the ROB assessment.
77 | 5 | 11) I greatly appreciate the comprehensive review of the existing literature in this report. Certainly, there is a need for more high-quality studies in the relevant populations of Veteran parents, and Veteran parents with histories of serious mental illness including PTSD and those with histories of sexual assault. Page 52, line 27, Table 6 is also very helpful. In the Discussion, it may be useful to expand on the last line of ‘Timing: Outcomes beyond 12 months’ and the implications of this gap in the literature. It might also be helpful to include the cited gaps below in the bulleted Key Findings box at the beginning of the Executive Summary (page 1, line 47): “We did not identify any studies conducted only among parents with PTSD” “Only 1 study was conducted exclusively with Veterans” | Thank you. We have revised the Executive Summary to highlight these critical gaps in the literature.
78 | 8 | Thank you for the additional time, and thank you for all that you’ve invested in this work. Please see track changes in the attached document.; A few summary points for consideration in addition to those detailed below and in the attachment include:; - The way SMI is defined for the purposes of this review would bear elaboration much earlier in the paper than it occurs. While I note that it is specified later that it includes PTSD and MDD, there is enough variability in what the term “SMI” encompasses that the reader would benefit from knowing how it is characterized specifically in this work as early in the document as possible. | Thank you for this comment. We have clarified in the Executive Summary that SMI includes PTSD and MDD. A complete description of how we define SMI is found in the Methods section of the report.
79 | 8 | - I am concerned about the use of Parenting STAIR in a way that makes it appear to be a gold standard approach that is already formally implemented within VA. In reality, Parenting STAIR is being piloted (not formally rolled out/nationally implemented) and evidence and applicability in published trials is limited. A related concern is the downgrading of evidence when it did not compare with Parenting STAIR. I am concerned that the act of downgrading may have changed the way some of the outcomes were considered. | We did not intend for the report to convey that Parenting STAIR piloted in the VHA was a gold standard approach. We have clarified this in the introduction. Also we have clarified how we are operationalizing indirectness for GRADE in the Methods and Discussion sections. We did not downgrade the evidence if it was not comparable to Parenting STAIR piloted in the VHA. Studies were downgraded if they had features that would make VA implementation more challenging (eg., direct involvement of child).
80 | 8 | I concur with the observation that, as currently written in the intro and future directions sections, military service is itself akin to a risk factor in parenting difficulties. We know that many military families are resilient (also noted in this report, p2) and I think focusing on the aspects of the parents that may be impacting parenting capacity and ability may not only be a helpful frame for this work, but also for future directions. | We have revised the introduction and discussion section to clarify that the central rationale for this report is on characteristics of the parent related to SMI and sexual trauma. Yet, military service is associated with many experiences that are often risk factors for parenting difficulties (family separations, stress, trauma), but these do not impact everyone the same way. As such, adapting parenting skill interventions to account for military service as a context can be a helpful future research direction.
81 | 8 | - There are aspects of family reintegration following deployment that may benefit from inclusion(comment on p.9 ), to provide additional context to the multiple stressors that affect families across the continuum of Veteran service eras. | Thank you. We have added reintegration as a family stressor.
82 | 8 | - Formatting observations:; - Outcomes of interest: Study selection section on p.2 gives examples of outcomes. It would be useful to the naïve reader to have an overview list or table of the outcomes considered across the studies allow for deeper understanding reading the report from the beginning. Figure 4 captures them nicely (starting p. 25) but an earlier overview would be better. | Thank you for this observation. Such information is typically not provided in the Executive Summary. We detail the outcomes in Table 1, PICOTS eligibility table, which is located on page 3 of the main report.
83 | 8 | Suggest reviewing all mentions of statistical significance as there was significant variability in how these were documented. Some used italicized values for p, d, others did not, etc. | We have addressed this inconsistency.