# APPENDIX F RISK OF BIAS ASSESSMENTS

## ROB 2 Risk of Bias Assessment for KQ2 Randomized Trials

## ROBINS-I Risk of Bias Assessment for KQ2 Nonrandomized Studies

## ROB 2 Risk of Bias Assessment for KQ3 Randomized Trials

## ROBINS-I Risk of Bias Assessment for KQ3 Nonrandomized Studies

## ROB 2 Risk of Bias Assessment for KQ4 Randomized Trials

## ROBINS-I Risk of Bias Assessment for KQ4 Nonrandomized Studies