# APPENDIX E PARENTING SKILLS INTERVENTION PROGRAM CONTENT DESCRIPTIONS

Intervention Skill | Description
Child development knowledge and care | Providing developmentally appropriate physical care and environment (eg, feeding, diapering, home safety); learning about typical child development and behavior; fostering children’s positive emotional development (eg, self-esteem, providing stimulating environment)
Positive interactions with child | Learning the importance of positive, non-disciplinary interactions with children; using skills that promote positive parent-child interactions (eg, demonstrating enthusiasm, following child’s interests, offering appropriate recreational options); providing positive attention
Responsiveness, sensitivity, and nurturing | Responding sensitively to child’s emotional and psychological needs (eg, soothing); providing developmentally appropriate physical contact and affection
Emotion communication | Using relationship-building communication skills (eg, active listening); helping children identify and appropriately express emotions
Disciplinary communication | Giving clear and developmentally appropriate directions; setting limits and rules; stating behavioral expectations and consequences
Discipline and behavior management | Attitudes about discipline strategies; attributions about child misbehaviors; monitoring and supervision practices; techniques, eg, planned ignoring, positive reinforcement, time out; specific reinforcement and punishment techniques; problem solving about child behaviors; consistent responding or generalization
Promoting children’s social skills or prosocial behavior | Educating parents to teach children to share and cooperate, use good manners, and get along with peers, siblings, or adults
Promoting children’s cognitive or academic skills | Using incidental teaching; fostering children’s language or literacy development; enhancing child’s school readiness

Notes. Source: Adapted from Kaminski et al 2008.^5^